# INTRODUCTION

Across the world, the adoption of robot-assisted surgery continues to increase, particularly for commonly performed general surgery procedures. In the US, the robot-assisted surgical platform was introduced in 1999 and by the end of 2017, over 3,000 robotic platforms were being used.^2^ While this new technology is becoming widespread, several questions about the utility of robot-assisted surgery as compared to laparoscopic and open surgery persist. In particular, does the use of the robot translate to better or similar clinical outcomes for patients? Are operating room times and length of stay comparable or improved with use of robot as compared to laparoscopic or open techniques? These questions are critical to answer, both for patient safety and satisfaction, particularly in our current health care climate where hospitals and physicians must provide efficient care while maintaining the highest quality, all the while working to curtail costs.

Cholecystectomy and hernia repair are commonly performed general surgery procedures. Over 1 million cholecystectomies and 800,000 ventral and inguinal hernia repairs are completed annually in the US.^3,4^ Robot-assisted approaches to these procedures are becoming more common and accepted.^5^ Specifically, inguinal and ventral hernia repairs are the most rapidly growing procedures for the robot-assisted platform in general surgery. For example, a cohort study from the Michigan Surgical Quality Collaborative Database shows an increase in robot-assisted surgery general surgery procedures from 1.8% to 15.1% between 2012-2018.^6^ In addition to multi-port laparoscopic and robot-assisted techniques, there has been a shift to single-port robot-assisted and laparoscopic approaches as well, which reduces the number of incisions for the patient.^7,8^

Further fueling this debate is the economics of the robotic platform. The robotic platform requires a significant upfront investment, an annual maintenance contract, and ongoing instrument purchases, not to mention staff and training costs, advertising, and infrastructure upgrade expenses. Weighing these costs relative to the potential benefits of the robot-assisted approach, such as reduced length of stay, complications, readmissions, or improved patient centered outcomes, is critical in our climate of needing to curtail rising health care costs.

In light of recent evidence in other surgical disciplines questioning the utility of the robotic platform, there is considerable need to understand the evidence surrounding the use of the robotic platform in general surgery. Few comprehensive systematic reviews addressing each of these procedures exist – specifically where the critical patient factors and technique differences are assessed.

In summary, common general surgery procedures make up a large volume of the annual operations performed in the US, and we are experiencing dramatic recent growth in the number of robot-assisted surgery cases within this field. Yet there is no consensus or guidelines on when to use this surgical approach, and such decisions are left up to individual practitioners. To help clinicians, patients, and policymakers decide between robot-assisted and other surgical approaches for cholecystectomy, inguinal or ventral hernia repairs, we were asked to conduct a systematic review of the literature.