# APPENDIX H CITATIONS FOR EXCLUDED PUBLICATIONS

## Cholecystectomy

### Comparison (n=4)

1 Ayloo, S., Y. Roh and N. Choudhury (2014). “Laparoscopic versus robot-assisted cholecystectomy: a retrospective cohort study.” [underlined: Int J Surg] 12(10): 1077–1081.25218366
2 Jeong, S. Y., J. W. Lee, S. H. Choi and S. W. Kwon (2018). “Single-incision laparoscopic cholecystectomy using instrumental alignment in robotic single-site cholecystectomy.” [underlined: Ann Surg Treat Res] 94(6): 291–297.29854706
3 Lim, C., G. Bou Nassif, E. Lahat, M. Hayek, M. Osseis, C. Gomez-Gavara, T. Moussalem, D. Azoulay and C. Salloum (2017). “Single-incision robotic cholecystectomy is associated with a high rate of trocar-site infection.” [underlined: Int J Med Robot] 13(4).
4 Morel, P., F. Pugin, P. Bucher, N. C. Buchs and M. E. Hagen (2012). “Robotic single-incision laparoscopic cholecystectomy.” [underlined: J Robot Surg] 6(3): 273–274.22956983

### No Outcome of Interest (n=4)

1 Aslam U, Amadi C, Goparaju A, Brathwaite CE, Adrales GL. Trends in Use of Robotic-Assisted Surgery for Inpatient Elective General Surgery in the United States, 2010–2015. Journal of the American College of Surgeons. 2019;229(4):S116.
2 Aslam U, Howell RS, Brathwaite CEM, Adrales G. Analysis of Outcomes for Elective Inpatient Robotic-Assisted, Laparoscopic, and Open General Surgery in the United States, 2010–2015. Journal of the American College of Surgeons. 2019;229(4):S88.
3 Norwick, P. M., S. Shaheen, J. Blebea, N. Conti, R. Heckburn, M. Zayout, J. Clements and M. Ghanem (2019). “Robotic vs standard laparoscopic cholecystectomy: Clinical outcomes.” [underlined: Surgical Endoscopy] 33: S397.
4 Sheetz KH, Claflin J, Dimick JB. Trends in the Adoption of Robotic Surgery for Common Surgical Procedures. JAMA Network Open. 2020;3(1).

### No Clinical Data (n=3)

1 Armijo, P. R., S. Pagkratis, E. Boilesen, T. Tanner and D. Oleynikov (2018). “Growth in robotic-assisted procedures is from conversion of laparoscopic procedures and not from open surgeons’ conversion: a study of trends and costs.” [underlined: Surg Endosc] 32(4): 2106–2113.29067582
2 Coca-Soliz, VS, R. C. Gooding, J. Hubbard and P. R. Corvo (2017). “Comparison of laparoscope versus da vinci robot on surgical site infections based on operation time and operator volume.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 31: S314.
3 Hirides, S. (2017). “Cholecystectomy using conventional lap, minilap needlescopic or robotic single-site approaches. A technical comparison.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 31(2): S235.

### Other (n=2)

1 Aziz, H., M. Zeeshan, R. R. Selby and M. R. Sheikh (2019). “Looking beyond laparoscopic cholecystectomy – Will robotic cholecystectomy be the new the gold standard in patients with advanced liver disease?” [underlined: HPB] 21: S31.
2 Lee, M. M., K. K. Seeras and J. J. Lim (2019). “Cost comparison of single site robotic and conventional laparoscopic cholecystectomy at a single institution.” [underlined: Surgical Endoscopy] 33: S395.

### Review/Editorial (n=8)

1 Awad, M. M. and J. W. Fleshman (2010). “Robot-assisted surgery and health care costs [10].” [underlined: New England Journal of Medicine] 363(22): 2174–2175.
2 Barbash, G. I. and S. A. Glied (2010). “New technology and health care costs - The case of robot-assisted surgery.” [underlined: New England Journal of Medicine] 363(8): 701–704.
3 Biglarian, S. and N. Katkhouda (2017). “Requesting Patient Characteristics for Readmissions Noted in “Single-site Robotic Cholecystectomy in a Broadly Inclusive Patient Population: A Prospective Study”.” [underlined: Ann Surg] 265(4): e34–e35.28266977
4 Brody, F. and N. G. Richards (2014). “Review of robotic versus conventional laparoscopic surgery.” [underlined: Surgical Endoscopy] 28(5): 1413–1424.24357422
5 Castellanos, A., J. Fazendin and L. Panait (2015). “Single-incision laparoscopic cholecystectomy.” [underlined: Clinical Liver Disease] 5(1): 5–7.31312434
6 Giulianotti, P. C. (2017). “Why I think the robot will be the future for laparoscopic cholecystectomies.” [underlined: Surgery] 161(3): 637–638.27989604
7 Lee, E. K., E. Park, W. O. Oh and N. M. Shin (2017). “CORRIGENDUM: Correction of the affiliation name. Comparison of the outcomes of robotic cholecystectomy and laparoscopic cholecystectomy.” [underlined: Ann Surg Treat Res] 93(4): 229.29094034
8 Newman, R. M., A. Umer and S. Ellner (2016). “Traditional Four-Port vs Single-Incision and Robotically Assisted Cholecystectomy: In reply to Bloomstone and colleagues.” [underlined: J Am Coll Surg] 223(1): 208.

### Duplicate (n=11)

1 Armijo, P. R., S. Pagkratis, E. Boilesen, T. N. Tanner and D. Oleynikov (2017). “Growth in robotic-assisted procedures is from conversion of laparoscopic procedures and not from open surgeons conversion: a study of trends and costs.” [underlined: Surgical endoscopy and other interventional techniques. Conference: 2017 scientific session of the society of american gastrointestinal and endoscopic surgeons, SAGES 2017. United States] 31: S31.
2 Balachandran, B., T. Mustafa, T. A. Hufford, K. Kochar, L. M. Prasad, S. Sulo and J. Khorsand (2016). “A comparative study of outcomes between single-site robotic and multi-port laparoscopic cholecystectomy: An experience from a tertiary care center.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 30: S258.
3 Charles EJ, Hunter Mehaffey J, Kane WJ, Hawkins RB, Tache-Leon CA, Yang Z. Robotic compared to laparoscopic cholecystectomy: A propensity matched analysis. Surgical Endoscopy and Other Interventional Techniques. 2018;32(1):S34.
4 Gonzalez AM, Verdeja JC, Rabaza JR, . Single incision cholecystectomy: Comparative study between laparoscopic, robotic and spider platforms. Surgical Endoscopy and Other Interventional Techniques. 2013;27:S274.
5 Grochola, L. F., C. Soll and S. Breitenstein (2018). “Robot-assisted single-site compared with laparoscopic single-incision cholecystectomy for benign gallbladder disease: results of a single-blinded randomized controlled trial.” [underlined: European surgical research. Europaische chirurgische forschung. Recherches chirurgicales europeennes] 59: 4-.
6 Grochola, L. F., C. Soll, A. Zehnder, R. Wyss, P. Herzog and S. Breitenstein (2018). “Robot-assisted versus laparoscopic single-incision cholecystectomy: results of a randomized controlled trial.” [underlined: Surgical endoscopy].
7 Grochola, L. F., C. Soll, A. Zehnder, R. Wyss, P. Herzog and S. Breitenstein (2018). “Robot-assisted single-site compared with laparoscopic single-incision cholecystectomy for benign gallbladder disease: results of a single-blinded randomized controlled trial.” [underlined: HPB] 20: S726.
8 Grochola, L. F., C. Soll, A. Zehnder, R. Wyss, P. Herzog and S. Breitenstein (2018). “Robot-Assisted Single-Site compared with laparoscopic single-incision cholecystectomy for benign gallbladder disease: Results of a single-blinded randomized controlled trial.” [underlined: Swiss Medical Weekly] 148: 4S.
9 Higgins, R. M., M. J. Frelich, M. E. Bosler and J. C. Gould (2016). “Cost analysis of robotic versus laparoscopic general surgery procedures.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 30: S243.
10 Kaminski, J. P., K. W. Bueltmann and M. Rudnicki (2014). “Robotic versus laparoscopiccholecystectomy: Does the end justify the means?” [underlined: Surgical Endoscopy and Other Interventional Techniques] 28: 262.
11 Newman, R. M., B. J. Bozzuto, J. L. Dilungo and S. J. Ellner (2014). “The surgical valueof nontraditional, minimally invasive gallbladder removal: Traditional 4 port vs single incision and robotically-assisted cholecystectomy.” [underlined: Journal of the American College of Surgeons] 219(4): e34.

## Inguinal Hernia Repair

### Comparison (n=2)

1 Edelman, D. (2018). “Is robotic inguinal hernia repair safe?” [underlined: Hernia] 22(1): S103.
2 Edelman, D. S. (2017). “Robotic inguinal hernia repair.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 31: S330.

### No Clinical Data (n=3)

1 Delgado, M., J. C. Quispe, K. Medani, C. Wang and E. Yung (2019). “A 5 year retrospective study comparing results of laparoscopic versus robotic inguinal hernia repair.” [underlined: Journal of Investigative Medicine] 67(1): 221.
2 McCoy, K., W. Symons, J. Clarke, M. Novack and M. Broderick (2018). “Open versus robotic inguinal hernia repair: Is there a superior approach?” [underlined: Surgical Endoscopy and Other Interventional Techniques] 32(1): S346.
3 Verduzco-Gomez, E., A. Badami and F. Sabido (2018). “Robotic inguinal hernia repair eliminates the need for post-operative narcotics and demonstrates lower post-operative pain scores.” [underlined: Hernia] 22(1): S183.

### No Outcome of Interest (n=6)

1 Armijo, P. R., S. Pagkratis, E. Boilesen, T. N. Tanner and D. Oleynikov (2017). “Growth in robotic-assisted procedures is from conversion of laparoscopic procedures and not from open surgeons conversion: a study of trends and costs.” [underlined: Surgical endoscopy and other interventional techniques. Conference: 2017 scientific session of the society of american gastrointestinal and endoscopic surgeons, SAGES 2017. United States] 31: S31.
2 Aslam U, Amadi C, Goparaju A, Brathwaite CE, Adrales GL. Trends in Use of Robotic-Assisted Surgery for Inpatient Elective General Surgery in the United States, 2010–2015. Journal of the American College of Surgeons. 2019;229(4):S116.
3 Aslam U, Howell RS, Brathwaite CEM, Adrales G. Analysis of Outcomes for Elective Inpatient Robotic-Assisted, Laparoscopic, and Open General Surgery in the United States, 2010–2015. Journal of the American College of Surgeons. 2019;229(4):S88.
4 Muysoms, F., C. Ballecer and A. Ramaswamy (2018). “Evaluation of the operative time for robotic assisted laparoscopic groin hernia repair during the learning curve of 125 cases.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 32(1): S144.
5 Sheetz KH, Claflin J, Dimick JB. Trends in the Adoption of Robotic Surgery for Common Surgical Procedures. JAMA Network Open. 2020;3(1).
6 Zayadin Y, D’John J, Yaldo B, McKany M. Urinary Retention Post Open vs Laparoscopic vs Robotic Inguinal Hernia Repair: A Comparative Retrospective Review. Journal of the American College of Surgeons. 2019;229(4):e129.

### Procedure (n=1)

1 Tran, H. (2011). “Robotic single-port hernia surgery.” [underlined: Jsls] 15(3): 309–314.21985715

### Systematic Review (n=1)

1 Jacks BE, Agor UJ, Sanni AO. Clinical Outcomes after Robotic Assisted Transabdominal Preperitoneal (R-TAPP) vs Laparoscopic Totally Extraperitoneal (L-TEP) Inguinal Hernia Repair. Journal of the American College of Surgeons. 2019;229(4):e109.

### Review/Editorial (n=2)

1 Bernhardt, G. A., K. Gruber and G. Gruber (2010). “TAPP repair in a giant bilateral scrotal hernia - limits of a method.” [underlined: ANZ J Surg] 80(12): 947–948.21114742
2 Godshall, E., S. Eckhouse, C. Johnson, A. Patterson and R. Pullatt (2015). “Transabdominal Preperitoneal Inguinal Hernia Repair as a Salvage Operation after Failure of Prior Total Extraperitoneal Repair.” [underlined: Am Surg] 81(8): 312–313.26215231

### Duplicate (n=3)

1 Hennings, D. L., P. R. Armijo and D. Oleynikov (2018). “Robotic inguinal hernia repair is superior to open or laparoscopic inguinal hernia repair: A national data base review.” [underlined: Surgical Endoscopy and Other Interventional Techniques] 32(1): S344.
2 Muysoms, F., C. Ballacer, A. Ramaswamy, S. Van Cleven and I. Kyle-Leinhase (2017). “Evaluation of the operative time for robotic assisted laparoscopic groin hernia repair during the learning curve.” [underlined: Hernia] 21(2): S159.
3 Zayan NE, Meara MP, Schwartz JS, Narula VK. A direct comparison of robotic and laparoscopic hernia repair: patient-reported outcomes and cost analysis. Hernia. 2019;23(6):1115–1121.31037492

### Unavailable (n=1)

1 Edelman, D. S. (2017). “Robotic Inguinal Hernia Repair.” [underlined: Am Surg] 83(12): 1418–1421.29336765

## Ventral Hernia Repair

### Comparison (n=6)

1 Halka, J., A. Vasyluk, A. DeMare, A. Iacco and R. Janczyk (2018). “Hybrid robotic assisted transversus abdominis release is associated with a significantly decreased length of stay without increased complications compared to open transversus abdominis release in patients with large ventral hernias.” [underlined: Hernia] 22(1): S27.
2 Halka, J. T., A. Vasyluk, A. Demare, A. Iacco and R. Janczyk (2019). “Hybrid robotic-assisted transversus abdominis release versus open transversus abdominis release: a comparison of short-term outcomes.” [underlined: Hernia] 23(1): 37–42.30456551
3 Muse, T. O., B. A. Zwischenberger, M. T. Miller, D. A. Borman, D. L. Davenport and J. S. Roth (2018). “Outcomes after Ventral Hernia Repair Using the Rives-Stoppa, Endoscopic, and Open Component Separation Techniques.” [underlined: Am Surg] 84(3): 433–437.29559061
4 Oviedo, R. J., J. C. Robertson and A. S. Desai (2017). “Robotic Ventral Hernia Repair and Endoscopic Component Separation: Outcomes.” [underlined: Jsls] 21(3).
5 Sailes, F. C., J. Walls, D. Guelig, M. Mirzabeigi, W. D. Long, A. Crawford, J. H. Moore, Jr., S. E. Copit, G. A. Tuma and J. Fox (2011). “Ventral hernia repairs: 10-year single-institution review at Thomas Jefferson University Hospital.” [underlined: J Am Coll Surg] 212(1): 119–123.21115373
6 Ioannidis A, Machairas N, Koutserimpas C, Spartalis E, Konstantinidis M, Konstantinidis K. Evolution of robot-assisted general surgery in Greece and Cyprus. Journal of Robotic Surgery. 2019;13(2):315–317.30536222

### No Outcome of Interest (n=7)

1 Addo AJ, Zahiri HR, Broda A, . Early Perioperative Outcomes in Obese Patients Undergoing Minimally Invasive Abdominal Wall Reconstruction. Journal of the American College of Surgeons. 2019;229(4):e112.
2 Armijo PR, Pagkratis S, Boilesen E, Tanner T, Oleynikov D. Growth in robotic-assisted procedures is from conversion of laparoscopic procedures and not from open surgeons’ conversion: a study of trends and costs. Surgical Endoscopy. 2018;32(4):2106–2113.29067582
3 Aslam U, Amadi C, Goparaju A, Brathwaite CE, Adrales GL. Trends in Use of Robotic-Assisted Surgery for Inpatient Elective General Surgery in the United States, 2010–2015. Journal of the American College of Surgeons. 2019;229(4):S116.
4 Aslam U, Howell RS, Brathwaite CEM, Adrales G. Analysis of Outcomes for Elective Inpatient Robotic-Assisted, Laparoscopic, and Open General Surgery in the United States, 2010–2015. Journal of the American College of Surgeons. 2019;229(4):S88.
5 Forester B, Donovan K, Kuchta K, . Short-Term Quality of Life Comparison of Laparoscopic, Open, and Robotic Incisional Hernia Repairs. Journal of the American College of Surgeons. 2019;229(4):e127.
6 Sheetz KH, Claflin J, Dimick JB. Trends in the Adoption of Robotic Surgery for Common Surgical Procedures. JAMA Network Open. 2020;3(1).
7 Zayan NE, Meara MP, Schwartz JS, Narula VK. A direct comparison of robotic and laparoscopic hernia repair: patient-reported outcomes and cost analysis. Hernia. 2019;23(6):1115–1121.31037492

### Sample Size (n<10) (n=2)

1 Belyansky, I., A. S. Weltz, U. S. Sibia, J. J. Turcotte, H. Taylor, H. R. Zahiri, T. R. Turner and A. Park (2018). “The trend toward minimally invasive complex abdominal wall reconstruction: is it worth it?” [underlined: Surgical Endoscopy] 32(4): 1701–1707.28917019
2 Mejia, A., C. G. Fasola and A. Stegall (2019). “Incisional ventral hernia repair (IVHR) in post liver transplant recipients (OLT) through a robotic-assisted intervention (RAI): Initial single-center experience.” [underlined: American Journal of Transplantation] 19: 863–864.

### Case series n<10 (n=2)

1 Daes, J. (2014). “Endoscopic subcutaneous approach to component separation.” [underlined: J Am Coll Surg] 218(1): e1–4.24161668
2 Gillespie, J. W., 3rd, D. D. Zabel, M. K. Conway, E. D. Kalish and D. E. Sarmiento Garzon (2015). “Abdominal Wall Reconstruction for Large Ventral Hernias in the Octogenarian.” [underlined: Am Surg] 81(11): E373–375.26672570

### Systematic Review (n=1)

1 Souza, J. M. and G. A. Dumanian (2012). “An evidence-based approach to abdominal wall reconstruction.” [underlined: Plast Reconstr Surg] 130(1): 116–124.22743878

### Review (n=1)

1 (2012). “Hernia repair: which surgical approach is best?” [underlined: Johns Hopkins Med Lett Health After 50] 24(8): 4–5.

### Duplicate (n=6)

1 Addo A, Parlacoski S, Ewart Z, Broda A, Zahiri R, Belyansky I. Comparative review of outcomes: Laparoscopic and robotic enhanced-view totally extraperitoneal rives-stoppa abdominal wall reconstruction. Surgical Endoscopy. 2019;33:S15. Alrefai, S., M. Mabe, M. Vy, P. Del Prado, N. L. Clingempeel and J. G. Bittner (2017). “Comparative analysis of robot-assisted minimally invasive vs open transvs abdomens release outcomes in abdominal wall reconstruction.” [underlined: Journal of the American College of Surgeons] 225(4): e83–e84.
2 Alrefai S, Mabe M, Vy M, Del Prado P, Clingempeel NL, Bittner JG. Comparative analysis of robot-assisted minimally invasive vs open transvs abdomens release outcomes in abdominal wall reconstruction. Journal of the American College of Surgeons. 2017;225(4):e83–e84.
3 Costa, T. N., R. Z. Abdalla, I. Cecconello and U. Ribeiro (2017). “Randomized clinical trial: Comparison between robotic assisted and laparoscopic incisional hernia repair.” [underlined: Hernia] 21(2): S158.
4 Khorgami, Z., T. Jackson, W. T. Li, C. A. Howard and G. M. Sclabas (2017). “Extra costs of robotic surgery in minor and major surgeries: An analysis of national inpatient sample.” [underlined: Journal of the American College of Surgeons] 225(4): e86.
5 Walker, P., A. May, M. R. Santillan, S. Kim, S. Shah, E. Wilson, M. Liang and S. Tsuda (2017). “Multicenter review of robotic versus laparoscopic ventral hernia repair: is there a role for robotics?” [underlined: Surgical endoscopy and other interventional techniques. Conference: 2017 scientific session of the society of american gastrointestinal and endoscopic surgeons, SAGES 2017. United states] 31: S29.
6 Weltz, A. S., J. Turcotte, U. S. Sibia, E. Zakharov, N. Wu, T. R. Turner, A. Park, H. R. Zahiri and I. Belyansky (2017). “The trend toward minimally invasive complex abdominal wall reconstruction: Is it worth it?” [underlined: Surgical Endoscopy and Other Interventional Techniques] 31: S22.

### Unavailable (n=1)

1 Espinosa-de-los-Monteros, A. (2012). “[Abdominal wall reconstruction for complex incisional hernias].” [underlined: Rev Invest Clin] 64(6 Pt 2): 634–640.23593782