# APPENDIX G EVIDENCE TABLES

## CHOLECYSTECTOMY

Demographics and Pre-operative Factors

Intra-operative Outcomes

Short-term Outcomes

Long-term Outcomes

## INGUINAL HERNIA REPAIR

## VENTRAL HERNIA REPAIR