# APPENDIX F QUALITY ASSESSMENT FOR INCLUDED OBSERVATIONAL STUDIES

## CHOLECYSTECTOMY

Author, year | Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result | Other source of bias
Abel, 2019^32^ | Serious: not discussed | Serious: unknown how offered | Low | Low | No information | Low | Low | n/a
Aggarwal, 2020^22^ | Low: no serious demographic differences | Low: surgical method based on scheduled surgery date | Low | Low | Low (short follow-up) | Low | Low | n/a
Albrecht, 2017^17^ | Low: matched | Moderate: unknown how offered | Low | Low | No information | Moderate: patient-reported pain scores | Low | n/a
Altieri, 2016^45^ | Low: propensity matching | Serious: unknown how offered, database | Low | Low | No information | Low | Low | n/a
Aragon, 2014^44^ | Moderate: differences in weight | Serious, unknown how offered | Low | Low | Low: no missing data | Low | Low | n/a
Autin, 2015^39^ | Serious: not discussed | Serious, unknown how offered | Low | Low | No information | Low | Moderate | n/a
Balachandran, 2017^23^ | Moderate: sig differences in gender, BMI, comorbidities, previous abdominal surgeries and diagnosis | Serious: unknown who was offered robotic vs lap | Low | Low | Low: excluded missing data | Low | Low | n/a
Buzad, 2013^33^ | Moderate: sig differences in gender | Serious for SILC: don’t know how they retrospectively chose cases; Low for SSRC: consecutive cases in that time frame | Low | Low | Low: no missing data | Low | Low
Calatayud, 2012^116^ | Low: similar groups | Serious: unknown who was offered robotic vs lap | Low | Low | No information | Low | Low | n/a
Chung, 2015^24^ | Moderate: sig differences in age, BMI, elective nature, ASA classification, hypertension | Moderate: unknown whether it was consecutive or all cases, unclear how offered | Low | Low | Low: excluded missing data | Low | Low | n/a
Eid, 2020^21^ | Serious: acuity of surgeries significantly diff between groups | Serious: unknown how offered | Low | Low | Low (short follow-up) | Low | Low | n/a
Farnsworth, 2018^46^ | Moderate: significant differences in primary diagnoses | Serious: prospectively collected ACS registry but don’t know how people were offered | Low | Low | No information | Low | Low | n/a
Farukhi, 2017^52^ | Serious: not discussed | Serious: unknown how offered | Low | Low | No information | Low | Low | n/a
Gonzalez, 2013^34^ | Moderate: sig differences in age and ASA score | Moderate: ALL robotic cases compared to first, consecutive 166 lap cases, but don’t know how offered | Low | Low | Low: account for missing data | Low | Low | n/a
Gustafson, 2016^36^ | Moderate: BMI and prior abd surgeries significantly diff | Moderate: consecutive cases but don’t know how offered | Low | Low | Low: no missing data | Moderate: pt reported outcomes | Low | n/a
Hagen, 2017^25^ | Low: patients matched by characteristic | Moderate: don’t know how offered but matched | Low | Low | Low: no missing data | Low | Low | n/a
Hagen, 2017^30^ | Low: case-matched analysis | Moderate, unknown how offered | Low | Low | No information | Low | Low | n/a
Hawasli, 2016^55^ | Moderate: age didn’t differ but didn’t discuss other sources of bias | Moderate: all cases in time period but didn’t discuss how offered | Low | Low | No information | Low | Low | n/a
Higgins, 2017^61^ | Serious: don’t discuss | Serious: unknown who was offered robotic vs lap | Low | Low | No information | Low | Low | n/a
Jang, 2019^40^ | Serious: gender, age, BMI and ASA score differences | Serious, unknown how offered | Low | Low | No information | Moderate: unknown who measured pain scale | Low | n/a
Kaminski, 2014^58^ | Moderate: shown but not analyzed differences in age, gender, race. Unsure of significant differences | Serious: unknown who was offered robotic vs lap | Low | Low | Low: excluded missing for outcomes of interest | Low | Low | n/a
Kane, 2020^57^ | Low, propensity-matched | Serious: unknown how offered | Low | Low | No information | Low | Low | n/a
Khorgami, 2019^49^ | Moderate: no differences, but lumped all surgeries together, no sub-analysis of just cholecystectomy | Serious: unknown who was offered robotic vs lap | Low | Low | No information | Low | Low | n/a
Lee, 2017^26^ | Moderate | Moderate: unknown who was offered robotic vs lap | Low | Low | Low | Moderate: patient-reported questionnaire | Low | n/a
Lee, 2018^41^ | Moderate: BMI, sex and indication differences | Serious: consecutively performed but unknown how offered | Low | Low | No information | Low | Low | n/a
Lee, 2019^27^ | Moderate: differences in age, ASA status, preop and pathologic diagnosis | Moderate: patient decided robot vs lap | Low | Low | No information | Low | Low | n/a
Lescouflair, 2014^42^ | Low: matched pts | Serious: consecutively performed but unknown how offered | Low | Low | No information | Moderate: pain measurements | Low | n/a
Li, 2017^28^ | Low: similar groups | Serious: unknown who was offered robotic vs lap | Low | Low | No information | Low | Low | n/a
Main, 2017^18^ | Moderate: propensity matched analysis, but differences in indication | Serious: unknown who was offered robotic vs lap | Low | Low | No information | Low | Low | n/a
Mitko, 2016^20^ | Moderate: indication different | Serious: reviewed all performed but unknown how offered | Low | Low | No information | Low | Low | n/a
Moore, 2016^43^ | Moderate: age different | Serious: consecutively performed but unknown how offered | Low | Low | No information | Low | Low | n/a
Pokala, 2019^56^ | Serious: groups sig diff in age and race | Serious: unknown how offered (database) | Low | Low | Low (short follow-up) | Low | Low | n/a
Rosemurgy, 2015^50^ | Serious: don’t discuss | Serious: unknown who was offered robotic vs lap | Low | Low | No information | Low | Low | Didn’t report surgical indication/diagnosis
Ross, 2014^53^ | Serious: no discussion | Serious: unknown how offered | Low | Low | No information | Low | Low | n/a
Spinoglio, 2012^37^ | Low, similar groups | Low, consecutive cases that matched inclusion criteria matched to 25 consecutive lap cases | Low | Low | Low: no missing data | Low | Low | n/a
Strosberg, 2017^51^ | Moderate: differences in BMI, comorbidities and indication | Serious, unknown how offered | Low | Low | Low: no missing data | Low | Low | n/a
Strosberg, 2017^51^ | Serious: BMI, comorbidities, indication different | Serious: unknown how offered | Low | Low | No information | Low | Low | n/a
Su, 2017^38^ | Low: similar groups | Serious, unknown how offered | Low | Low | Low: no missing data | Moderate: unknown who measured pain scale | Low | n/a
Teoh, 2017^31^ | Moderate: similar groups but not addressed what was measured | Serious: unknown how offered | Low | Low | No information | Moderate: unknown who measured pain scale | Low | n/a
Wren, 2011^29^ | Low: average age and BMI not significantly different | Moderate: robot offered to all who met inclusion/exclu sion criteria and compared to previous sequential lap cases | Low | Low | Low: no missing data | Moderate: pain measurement | Moderate: excluded 1 patient who had conversion | n/a

## INGUINAL HERNIA REPAIR

Author, year | Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result | Other source of bias
Abdelmoaty, 2018^75^ | Serious: no baseline characteristics reported | Low: database | Low | Low | Low | Low | Low | 1 author is a surgical proctor for Intuitive
AlMarqoozi, 2019^71^ | Low: similar baseline characteristics and laterality except for age; non-propensity matched | Low: database | Low | Low | Serious: Low 1-yr f/u (6-9%) | Low: complications; Moderate: QOL | Low | 2 authors (including senior author) receive grants from Intuitive
Bittner, 2018^12^ | Moderate: cohorts differed by age, type of job, history of IHR, and use of preop pain meds; BMI not reported but propensity matched | Serious: random consumer sample with, only includes those with survey completion | Serious: recall bias due to study design | Low | Serious: low survey response rate (6%) | Serious: narcotic use, RTW, pain | Low | Study funded by Intuitive; 2 authors (including senior author) employed by Intuitive; 1 author receives consulting fees from Intuitive
Charles, 2018^68^ | Moderate: similar baseline characteristics except ASA; non-propensity matched | Low: database | Low | Low | Low | Low: complications, OR times | Low | 1 author with grant and travel expenses for educational course from Intuitive
Gamagami, 2018^69^ | Low: similar baseline characteristics; propensity matched | Low: consecutive series | Low | Low | Low | Low: complications; Moderate: pain not well-defined | Low | Study sponsored by Intuitive; statistical analysis performed by Intuitive; all authors received research grants from Intuitive; 4 authors received consulting and education fees from Intuitive
Holcomb, 2019^84^ | Serious: most demographic data not displayed; non-propensity matched | Low: database | Low | Low | Low | Low: complications | Low
Huerta, 2019^70^ | Serious: differs in laterality and hernia complexity; non-propensity matched | Moderate: patients chosen by surgeon expertise | Low | Low | Low | Low: inguinodynia, complications | Low
Janjua, 2020^77^ | Low: differences in age, gender, comorbidities, and laterality; propensity matched | Low: database | Low | Low | Low | Low: LOS | Low
Kakaishvili, 2018^72^ | Serious: baseline characteristics not specified, laterality differs; non-propensity matched | Serious: not specified if consecutive series | Low | Low | Low | Low: OR times, complications; Moderate: pain | Low
Khoraki, 2019^78^ | Low: similar baseline characteristics; non-propensity matched | Low | Low | Low | Low | Low: complications | Low
Knott, 2017^80^ | Serious: not propensity matched, adjusted for patient characteristics but not displayed | Low: database | Low | Low | Moderate: unknown follow-up | Low | Low
Kolachalam, 2017^66^ | Low: similar characteristics, propensity matched | Low: consecutive series for robotic group; Moderate: open group patients prior to study initiation | Low | Low | Low | Low | Low | Study sponsored by Intuitive; statistical analysis performed by Intuitive biostatistician; all authors received research grants from Intuitive; 4 authors received consulting and education fees from Intuitive
Kosturakis, 2018^67^ | Serious: baseline characteristics differ in hernia laterality and ASA; non-propensity matched | Low: consecutive series | Low | Low | Moderate: unknown follow-up | Low | Low
Kudsi, 2017^74^ | Serious: similar baseline characteristics and laterality except gender and ASA; non-propensity matched | Low: consecutive series | Low | Low | Moderate: missing some data in robot group at f/u | Low: complications, inguinodynia | Low | 1^st^ author is consultant for Intuitive
Lammers, 2019^83^ | Serious: similar baseline characteristics but not reported; non-propensity matched | Low: consecutive series | Low | Low | Low | Low: OR times, complications | Moderate: spread not reported
Macias, 2017^81^ | Serious: baseline characteristics and laterality not reported | Serious: not specified if consecutive series | Low | Low | Moderate: unknown follow-up | Low: OR times, inguinodynia | Moderate: limited perioperative and long-term outcomes reported
Muysoms, 2018^73^ | Moderate: similar patient characteristics except baseline QOL, laterality analyzed in subgroups; non-propensity matched | Low: consecutive series for robot Moderate: lap patients from previously published studies | Low | Low | Low | Low: OR times, complications; Moderate: QOL/pain | Low | 1^st^ author receives consultant fees from Intuitive
Pokala, 2019^82^ | Serious: baseline characteristics not completely reported; robot patients more male; non-propensity matched | Moderate: database, severe severity excluded | Low | Low | Low | Low: complications, pain | Low
Sheldon, 2019^79^ | Moderate: similar baseline characteristics except for laterality, other characteristics not reported; non-propensity matched | Serious: institutional data, not stated if consecutive series; patients with intraoperative conversions of approach excluded | Low | Low | Low | Low: narcotic use | Low
Switzer, 2019^64^ | Serious: similar baseline demographics, baseline QOL scores, laterality, but not explicitly reported; non-propensity matched | Serious: database; excluded patients without 6-mo EuraHS | Low | Low | Low | Low: complications, readmissions, recurrences; Moderate: EuraHS QOL | Moderate: complications not specified
Waite, 2016^65^ | Low: similar baseline characteristics, laterality | Low: consecutive series | Low | Low | Low | Low: OR times; Moderate: pain scale | Low | 1 author became a consultant for Intuitive following preparation of manuscript
Zayan, 2019^76^ | Serious: differ by gender, smoking status, comorbidities, and laterality; non-propensity matched | Serious: not stated if consecutive series, selected based on availability to complete 1-yr f/u survey | Low | Low | Low | Low: LOS, OR times, complications; Moderate: QOL | Moderate: limited reporting of complications

## VENTRAL HERNIA REPAIR

Author, year | Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result | Other source of bias
Altieri, 2018^99^ | Moderate: differences in ethnicity, gender, BMI; propensity matched but characteristics not reported | Low: database | Low | Low | Low | Low: complications | Moderate: matched outcomes poorly reported and inconsistent with tables
Armijo, 2018^104^ | Moderate: similar characteristics except gender and comorbidities; non-propensity matched | Low: database | Low | Low | Low | Low: narcotic use, complications | Low
Bittner, 2018^86^ | Serious: differences in co-morbidities, smoking status, gender, hernia size; non-propensity matched | Low | Low | Low | Low | Low: complications | Moderate: no data on recurrences at 90 days | 1^st^ author is consultant for Intuitive
Carbonell, 2018^90^ | Low: similar characteristics, including proportion of TARs performed; propensity matched | Low: database | Low | Low | Low | Low: complications | Low | 6 authors (including 1^st^ author) received honoraria from Intuitive; 2 authors received educational funds from Intuitive
Chen, 2016^100^ | Moderate: similar characteristics except for gender; non-propensity matched | Low | Low | Low | Low | Low: complications, recurrence | Low
Coakley, 2017^98^ | Low: similar baseline characteristics; non-propensity matched | Low: database | Low | Low | Low | Low: complications | Low
Gonzalez, 2015^95^ | Low: similar baseline characteristics; non-propensity matched | Low | Low | Low | Moderate: unknown follow-up | Low: complications, recurrence | Low
GuzmanPruneda, 2020^91^ | Serious: large difference in gender, smoking status, hernia size; non-propensity matched | Low: database | Low | Low | Low | Low: complications, recurrence; Moderate: QOL | Low | Operative techniques (eg drain placement) were significantly different between comparison groups
Khorgami, 2018^94^ | Serious: unable to assess characteristics, as data was pooled for multiple procedures; non-propensity matched | Low: database | Low | Low | Low | Low: LOS | Serious: no other outcomes besides LOS
Lu, 2019^93^ | Moderate: similar baseline characteristics except for gender and co-morbidities; non-propensity matched | Low | Low | Low | Serious: large difference in 1-year follow-up rates between groups | Low: complications, recurrence | Low | Senior author has received honoraria for speaking engagements and consulting for Intuitive
Martin-del-Campo, 2018^87^ | Low: similar baseline characteristics except ASA; propensity matched for hernia size | Low | Low | Low | Low | Low: complications | Low | 2 authors are consultants for Intuitive
Mudyanadzo, 2020 | Serious: baseline characteristics not reported; non-propensity matched | Serious: institutional data, not stated if consecutive series | Low | Low | Low | Low: pain, narcotic use | Low
Nguyen, 2017^88^ | Moderate: similar characteristics except hernia size; non-propensity matched | Serious: institutional data, not stated if consecutive series | Low | Low | Low | Low: complications | Low
Prabhu, 2017^96^ | Low: similar baseline characteristics; propensity matched | Low: database | Low | Low | Low | Low: complications | Low | 1^st^ and senior authors receive grant money from Intuitive
Roberts, 2019^92^ | Serious: significantly different hernia defect size, other baseline characteristics not reported; non-propensity matched | Low: database | Low | Low | Low | Low: pain, complications | Low
Song, 2017^103^ | Moderate: characteristics not explicitly reported; propensity matched | Low: database | Low | Low | Low | Low: complications, narcotic use | Low
Switzer, 2017^89^ | Moderate: similar age, gender, hernia size, other characteristics not explicitly reported; propensity matched | Low: database | Low | Low | Moderate: unknown follow-up | Low: complications, recurrence; Moderate: QOL | Moderate: complications outcomes not defined or reported
Walker, 2018^97^ | Moderate: similar baseline characteristics except gender; propensity matched except for gender, and matched characteristics not reported | Serious: institutional data, not stated if consecutive series | Low | Low | Moderate: unknown follow-up | Low: complications, recurrence | Moderate: matched outcomes only selectively reported | 2 authors (including senior author) receive honoraria to proctor for Intuitive
Warren, 2016^101^ | Serious: similar characteristics except gender, recurrent hernia, and whether TAR performed concurrently; non-propensity matched | Low: database | Low | Low | Low | Low: narcotic use, complications | Low | 1^st^ and senior authors are speakers for Intuitive
Zayan, 2019^76^ | Serious: difference in gender, BMI, smoking status, baseline QOL; non-propensity matched | Serious: institutional data, not stated if consecutive series | Low | Low | Moderate: unknown follow-up | Low: recurrence; Moderate: QOL | Moderate: no outcomes relating to other complications