# APPENDIX E QUALITY ASSESSMENT FOR INCLUDED RCT STUDIES

## CHOLECYSTECTOMY

Author, year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data | Selective reporting | Other sources of bias
Grochola, 2019^13^; Intraop | ○ | ⯋ | ● | ⯋ | ○ | ○ | ○
Patient measures | ○ | ⯋ | ○ | ○ | ○ | ○ | ○
Heemskerk, 2014^14^ | ⯋ | ⯋ | ⯋ | ⯋ | ○ | ○ | ●
Kudsi, 2017^15^ | ○ | ○ | ⯋ | ● | ○ | ○ | ○
Pietrabissa, 2016^16^ | ○ | ○ | ○ | ○ | ○ | ○ | ○

○= low risk of bias ● = risk of bias ⯋ = unknown

## INGUINAL HERNIA REPAIR

Author, year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data | Selective reporting | Other sources of bias
Prabhu 2020^63^ | ○ | ⯋ | ●; Single-blinded | ⯋ | ○ | ○ | ●; Intuitive funded institutional research grant to 1^st^ author; 6 authors received honoraria from Intuitive (including 1^st^ author)

○ = low risk of bias ● = risk of bias ⯋ = unknown