# APPENDIX D RISK OF BIAS IN NON-RANDOMISED STUDIES – OF INTERVENTIONS (ROBINS-I)

Bias domains included in ROBINS-I^10^

Pre-intervention | Risk of bias assessment is mainly distinct from assessments of randomised trials
Bias due to confounding | Baseline confounding occurs when 1 or more prognostic variables (factors that predict the outcome of interest) also predicts the intervention received at baseline; ROBINS-I can also address time-varying confounding, which occurs when individuals switch between the interventions being compared and when post-baseline prognostic factors affect the intervention received after baseline
Bias in selection of participants into the study | When exclusion of some eligible participants, or the initial follow-up time of some participants, or some outcome events is related to both intervention and outcome, there will be an association between interventions and outcome even if the effects of the interventions are identical; This form of selection bias is distinct from confounding—A specific example is bias due to the inclusion of prevalent users, rather than new users, of an intervention
At intervention | Risk of bias assessment is mainly distinct from assessments of randomised trials
Bias in classification of interventions | Bias introduced by either differential or non-differential misclassification of intervention status; Non-differential misclassification is unrelated to the outcome and will usually bias the estimated effect of intervention towards the null; Differential misclassification occurs when misclassification of intervention status is related to the outcome or the risk of the outcome, and is likely to lead to bias
Post-intervention | Risk of bias assessment has substantial overlap with assessments of randomised trials
Bias due to deviations from intended interventions | Bias that arises when there are systematic differences between experimental intervention and comparator groups in the care provided, which represent a deviation from the intended intervention(s); Assessment of bias in this domain will depend on the type of effect of interest (either the effect of assignment to intervention or the effect of starting and adhering to intervention).
Bias due to missing data | Bias that arises when later follow-up is missing for individuals initially included and followed (such as differential loss to follow-up that is affected by prognostic factors); bias due to exclusion of individuals with missing information about intervention status or other variables such as confounders
Bias in measurement of outcomes | Bias introduced by either differential or non-differential errors in measurement of outcome data. Such bias can arise when outcome assessors are aware of intervention status, if different methods are used to assess outcomes in different intervention groups, or if measurement errors are related to intervention status or effects
Bias in selection of the reported result | Selective reporting of results in a way that depends on the findings and prevents the estimate from being included in a meta-analysis (or other synthesis)