# APPENDIX B PEER REVIEWER COMMENTS AND RESPONSES

Reviewer comment | Authors Responses
| Note to the reviewers, we updated our search through April 2020. This added a handful of studies (5 cholecystectomy; 4 inguinal hernia repair; 4 ventral hernia repair). 1 inguinal study is an RCT. These did not change our main conclusions.
Yes - Throughout this very well written manuscript there is a biased assumption that the capabilities of surgeons operating laparoscopically and robotically are similar. This would be the majority view but I strongly believe that it is incorrect. Robotic instruments and integrated real 3 dimensional vision generated by 2 cameras, 1 for each eye is vastly different than laparoscopy. | Yes. We agree that the robot offers clear advantages and have added comments about these to the Discussion.; Thanks for your other comments. We expanded our Discussion section on: increased OR time/safer; complexity of cases; learning curves.
Could robotic procedures be longer because surgeons are seeing better and working safer? Could robotic procedures take longer because more complex cases are being performed?; Are robotic procedures taking longer because the staff are less experienced?; Where are robotic surgeons in their learning curves within all of these studies? Laparoscopy has been main stream for more than 30 years so the experience of surgeons with laparoscopy would have to be significantly higher.
Yes - As the authors know, the topic of robotic use in General Surgery is a very fluid and hot topic. Because the literature is continually changing with new studies, albeit, not RCTs, it is really difficult to make definitive conclusions. There was a recent study in the last 6 months comparing robotic and laparoscopic ventral hernia repair and concluded no difference in outcomes studied. The outcome that is not typically included in most studies is postoperative pain for all 3 procedures. Many experts feel the major benefit of robotic repair of both incisional and inguinal hernias is the avoidance of using tacks. The ability to use intra-corporal sewing with the robot for securing mesh with ventral hernias and avoiding tacks does reduce postop pain. Similarly, the use of mesh that eliminates the need for sutures for robotic inguinal hernia repair definitely reduces acute and chronic pain for these patients. So perhaps comments in these 2 areas would be helpful for the reader. I agree with the authors that it is really hard to justify by any outcome that there is a benefit to using a robot for cholecystectomy.; Compliments to the authors for an excellent review. Suggest you convert this into a manuscript that could be published in a surgical journal. | Yes. Thank you for your suggestion. We added comments to our Discussion about 1) benefit of robotic approach for hernia repairs as tacks aren’t used; 2) sutureless mesh.; Thank you for this comment. We are working several manuscripts to submit.
Edits recommended as below:; Page 4, Lines 32-40: Degrees/titles edited; recommend deletion of mailstops (10NC2); Mark A. Wilson, MD, PhD; National Director of Surgery (10NC2); Department of Veterans Affairs; William Gunnar, MD; Executive Director, National Center for Patient Safety; Former National Director of Surgery (10NC2); Department of Veterans Affairs | Thank you for your edits. These corrections were made.
Page 6, Lines 25-44: Capitalization is not consistent. Standardize terminology to robot-assisted for all uses.; RESULTS; …………………………………………………………………………………………………………………. 19; Key Question 1A - Cholecystectomy: What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic surgery for cholecystectomy?…………………..23; Key Question 2A - cholecystectomy: what is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic surgery for cholecystectomy? ……………………………… 30; Key Question 1B - inguinal hernia surgery: What is the clinical effectiveness of robot-assisted surgery compared to conventional laparoscopic or open surgery for inguinal hernia repair? 38 Key Question 2B - Inguinal Hernia Surgery: what is the cost-effectiveness of robotic-assisted surgery compared to conventional laparoscopic OR open surgery for inguinal hernia repair? …………………………………………………………………………………………………………………………………. 47; Key Question 1C - VentraL hernia surgery: What is the clinical effectiveness of robotic assisted surgery compared to conventional laparoscopic or open surgery for ventral hernia repair?………………………………………………………………………………………………………………………. 49; Key Question 2C - Ventral Hernia Surgery: what is the cost-effectiveness of robot-assisted surgery compared to conventional laparoscopic OR open surgery for ventral hernia repair? 59 | These corrections were made.
Page 8, Lines 39-33: Delete mailstops (10NC2); add current title for Dr. Gunnar as below:; This topic was developed in response to a nomination by Dr. Mark Wilson, National Director of; Surgery (10NC2), and Dr. William Gunnar, Executive Director, National Center for Patient Safety and former National Director of Surgery (10NC2). Key questions were then developed with input from the topic nominator, the ESP coordinating center, the review team, and the technical expert panel (TEP).
Very nice review. I have a couple minor edits/suggestions. | Requested edits were made to pages 7-8.
Page 7, line 42 would add …. We assessed robotic and laparoscopic approach for cholecystectomy, as open cholecystectomy is typically performed for cancer pathology or in the setting of significant inflammation or adhesive disease. | For page 41 comment: These studies reported inpatient and outpatient LOS so both were listed. We now display only outpatient values which generalizes better to how most are done.; We added a clarification that inguinal hernias and cholecystectomy are mainly outpatient procedures.
page 7 line 49 ,…in order (to) lessen confounding factors
page 8 line 20. not sure what is meant by “technique factors”….
page 41 line 11 - I think there are extra tick marks for length of stay.
I suspect that the learning curve of robotic general surgery played a large part in increased operative times. Most of the studies compared early surgeon experience with the robot compared with years of experience laparoscopically. Perhaps a reference about learning curve and robotic surgery could be included.
Inguinal hernia repairs and cholecystectomies rarely require inpatient hospitalization. This should be noted.
Robotic surgery is an exciting field with more advanced procedures being performed daily. Although the technology has been available for years there is still a learning curve for the surgeon and may be reflected by longer case times initially. As it becomes more integrated into practice I foresee the benefits will rise. This review is a great resource for those interested in robotic general surgery and how it compares to laparoscopic and open surgery. The authors skillfully reviewed many studies and have put together a comprehensive overview of the data we have thus far. Thank you for acknowledging the limitations of all these heterogenous studies.; Page numbers based on pdf document, not those printed on the text.; Cholecystectomy:; Did the studies look at difficulty of gallbladder surgery? Ie were the robotic gallbladders done because of an expected difficult surgery vs laparoscopic technique? This is alluded to further in the discussion as a selection bias.; Inguinal hernias:; Pg 11: Again was the difficulty of the hernias looked at in the demographics and case matching? I would always choose a robotic repair over laparoscopic if expected to be difficult (patient obesity, size of hernia defect, incarceration, bowel involvement).; Since the cost effectiveness sections all came to the same conclusions perhaps they could be condensed into 1 section.; Discussion:; Differences in OR time across studies is possibly due to docking time of the robot but an efficient team can do this in 10 minutes or less. I would also be careful placing a lot of weight on the differences in OR time especially if not a great time difference between technique. Faster is not necessarily better for the patient. I think a lot of the difference is due to the learning curve with starting robotic surgeries, the efficiency of the OR team and mostly the difficulty of the case. When choosing a surgical technique for hernia or gallbladder I always consider the robot when I anticipate a case to be more difficult. Ie larger hernia, incarcerated bowel, recurrence hernia, chronic cholecystitis with PCT. These cases will always take me longer because of the difficulty not because of the robot.; The LOS is a hard measure to compare as most of these cases are done outpatient regardless of technique. Again I don’t think there is a big clinical impact here but all the studies mention it.; As for the cost I agree that no conclusions can be made based on the evidence. These sections could be condensed into 1 for cholecystectomy and hernias.; Does the VA have any cost data to look at internally?; “Urologic surgery has been widely adopted in the VA, so this experience for the staff may translate into an easy implementation to the robotic general surgery field.” I agree with this statement. Most OR staff is familiar with robotic surgery and adept at use.; Research Gaps:; Agree with surgeon learning curve affecting outcomes of studies. Additionally the difficulty of cases effects outcomes.; Agree with need for long term follow up to prove hernia recurrence is lower or higher for each technique.; Cholecystectomy for cancer should be considered on its own for clinical effectiveness. This operation may involve a partial hepatectomy depending on pathology.; Additionally studies need to clearly compare cases based on the difficulty as I mentioned earlier. A small ventral hernia with no adhesions or bowel involvement can be done in 1-2 hours, whereas a larger ventral hernia with need for adhesiolysis and component release will take 3-5 hours.; Surgeon experience is a critical component in deciding which technique to use. At the end of the day the best operation for the patient is the 1 the surgeon is most experienced with.; I do not foresee many RRT being done for robotic vs laparoscopic vs open surgery in the future. The robotic surgery platform is taking off and has been proving itself without these trials. | Thanks for the comments. We added to the Discussion more specifics about the potential learning curve.; It is possible that more complex gallbladder cases are preferentially done with the robot, but this was hard to assess with the studies as case complexity wasn’t defined well for the benign disease. RCTs for cholecystectomy should control reasonably well for this potential difference. We also added comments about use of robot for more complex cases including cancer in the Discussion.; We added more cost data and have chosen to present them by the individual procedures. Cost range is quite different between these groups so it seems better to keep them separate.; Differences between study arms for hernias were multi-factorial. Sometimes matching was on patient factors, but not for hernia size or complexity. And sometimes visa versa. Standardized matching across studies on the most pertinent factors would be very useful. Studies typically matched based on the available variables available in their dataset. This comment was added to our Discussion as well. We added comments to address your points - gallbladder difficulty was poorly assessed for observational studies.; Yes. The difficulty of cases for inguinal hernias was also hard to assess. Particularly for inguinal hernias, there were gaps in reported information to assess. We did our best to control for laterality (unilateral, bilateral) as this would greatly impact outcomes we were interested in.; Unfortunately, we are not aware of any cost data within the VA. We are in the process of accessing VA utilization data on robotic surgery. A comment on this was added to the Discussion section.
This is an exhaustive review and is balanced well with the exception of the bias that I perceive as described above. It is clear that the authors have worked very dilligently to use language that avoids this bias against robotics but I would consider adding a section related to the expanded capabilities that robotic surgery has offered. | Thanks for the comment. We added text about the expanded capabilities of robotic surgery to the Discussion section.; We added to the Discussion the importance of balancing added cost with potential benefits to the patient.
For example lap inguinal hernias nation wide never exceeded 20% of total cases. However, with the addition of robotically trained inguinal hernia surgeons large markets, not just individual surgeons, now are able to offer minimally invasive inguinal hernia surgery to greater than 40% of an entire market. Personally, I saw my busy inguinal practice go from 60%mis 40%open to 95%MIS vs 5%open with the addition of the robotic platform to my armamentarium of procedures that I may thoughtfully offer to patients. The end result is that more patients are able to have an MIS hernia repair and this increased cost is worth it to each patient that has shorter times of lifting restrictions, less opioid utilization, earlier return to full activity, and earlier return to work.
The authors should be commended for synthesizing a large amount of data that stems from very disparate data sources with variable methodologies and end points. The authors appropriately used the GRADE methodology to rate the quality of the evidence. They also appropriately noted that data was too heterogenous to allow for meta-analysis and instead presented this as a systematic narrative review of the evidence. The authors clearly delineated their search strategy and analytic framework. They also note limitations in the study, including the learning curve effect of robotic surgery as the newer technology which may predispose towards higher costs and longer operative times for the newer procedures. The authors do address risk of bias in the published data but primarily discuss this in terms of publication bias and not selection or author bias. There is excellent literature that suggests that there is significant bias in published reports of robotic surgery, and specifically that studies with unreported Conflict of Interest are significantly more favorable towards robotics (example: https://www.ncbi.nlm.nih.gov/pubmed/28700443) | Excellent point, we have added a sentence about the evolution of the robotic platform to other companies and types of technology.; Thank you for your comment. We have added these additional gaps in the Discussion.; We added several additional research gaps to the Discussion, including the ones listed here: surgeon ergonomics, surgical education, learning curve, and anticipated new robotic platforms.
The data seems clear that robotic surgery takes longer. There are some limited indications that a few selected patient outcome metrics are improved with robotics compared to open surgery and that conversion to open surgery may be less often needed in robotics compared to laparoscopy. There is 1 area were robotic surgery seems to be have clinically worse outcomes, notably single port robotic surgery leading to higher incisional hernia rates compared to multiple port laparoscopy. Because the studies were selected as RCTs or case comparisons, the data sources are unable to answer an important question of whether robotics allows some cases to be done via a minimally invasive approach as opposed to an open approach. Robotic advocates often claim that the robot allows some procedures to be done minimally invasively instead of open, but some market data in hernia surgery suggests that more cases seem to be converting from laparoscopic to robotic, as opposed to open cases transitioning to robotic. Studies looking at market adoption of robotic surgery could help answer this question, but would require an additional avenue of analysis. Costs seem to be higher in robotics, but due to limitations in data and methodology this is less certain, and likely varies depending on the particulars of an operation and the method of accounting. For example, the costs of robotic acquisition are handled variably across studies, as is the cost of length of stay data.; The authors use their systematic review to identify 4 areas with a research gap as a guide to future research. These areas are well considered and are all worthy of future study. Because the literature review focused on patient outcomes and cost, the identified research gaps are obviously focused on these areas. There are several major research gaps not identified in this review as they do not directly arise in the types of studies considered in this analysis:; 1) Surgeon ergonomics and workload. Surgeons have a very high rate of musculoskeletal disorders due to the ergonomic challenges of both open and laparoscopic surgery. Advocates for robotic surgery often allege that ergonomics are improved and surgeon stress/workload/fatigue is decreased with robotic adoption, and postulate that this will result in improved surgeon longevity. Although data in this area is sparse, it would be a valuable additional area for future research.; 2) Surgical education and learning curve. Robotics is a new and evolving technology. This is creating major issues in surgical education - both in education of surgical trainees and also in education of surgeons in practice who are learning new approaches. The advent of laparoscopy more than 20 years ago showed the importance of education and learning curves, as patient injury rates skyrocketed during the early years of laparoscopic surgery.; 3) Future innovation in surgical robotics. Although not discussed in the review, all of the studies addressed here are using the da Vinci system from Intuitive. There are several new robotic platforms that will soon be available, and these will come with new opportunities and challenges with regard to technical issues, patient outcomes, and costs. Additionally, robotic platforms offer the potential for new advances in computer vision, machine learning, and automation that may transform the surgical landscape. These are areas rife with research opportunities.