# APPENDIX A SEARCH STRATEGIES

## CHOLECYSTECTOMY

### DATABASE SEARCHED & TIME PERIOD COVERED

Pubmed – 2010-2020

“Robotic Surgical Procedures”[Mesh] OR robotics[mh] OR robot-assisted OR robot*[tiab] OR robot*[ot]

AND

cholecystectomy[tiab]OR cholecystectomies[tiab])) OR cholecystectomy[MeSH]

AND

“2010”[Date - Publication] : 2020[Date - Publication]

### DATABASE SEARCHED & TIME PERIOD COVERED

EMBASE – 2010-2020

‘robot assisted surgery’/exp OR ‘robot assisted surgery’ OR ‘robot assisted’ OR robot*

AND

Cholecystectomy/exp OR Cholecystectomy OR Cholecystectomies

AND

Publication years 2010-2020

### DATABASE SEARCHED & TIME PERIOD COVERED

Cochrane 2010-2020

Robotic assisted surgical procedures OR robotics OR (MESH descriptor)Robotic Surgical Procedures/exp OR (MESH descriptor)Robotics/exp

AND

(MESH Descriptor)Cholecystectomy/exp OR (Cholecystectomy OR Cholecystectomies)ti,ab,kw

AND

Publication years Jan 2010-Dec 2020

## INGUINAL HERNIA

### DATABASE SEARCHED & TIME PERIOD COVERED

PUBMED – 2010-2020

“Robotic Surgical Procedures”[Mesh] OR robotics[mh] OR robot-assisted OR robot*[tiab] OR robot*[ot]

OR

surgical mesh or open surgical technique* or open operative technique* or open suture repair* or mesh repair*

OR

“Abdominal Wall/surgery”[Mesh] OR “Hernia, Ventral/surgery”[Mesh]

AND

Hernia, Inguinal[MESH] OR “inguinal hernia” OR “inguinal hernias” OR Groin[MESH] OR Groin or groins

AND

(limit) Humans

AND

(limit) adult

AND

“2010”[Date - Publication] : “2020”[Date - Publication]

### DATABASE SEARCHED & TIME PERIOD COVERED

EMBASE – 2010 - 2020

‘robot assisted surgery’/exp OR ‘robot assisted surgery’ OR ‘robot assisted’ OR robot*

AND

‘inguinal hernia/exp OR inguinal region/exp OR “inguinal hernia” OR “inguinal hernias” OR groin OR groins

AND

Human/de

AND

adult/lim OR aged/lim OR very elderly/lim

AND

Publication years 2010-2020

### DATABASE SEARCHED & TIME PERIOD COVERED

COCHRANE Reviews – 2010- Dec 2020

Robotic assisted surgical procedures OR robotics OR (MESH descriptor) Robotic Surgical Procedures/exp OR (MESH descriptor)Robotics/exp

AND

1. explode inguinal hernia (MeSH)
2. inguinal herni* ti,ab,kw
3. shouldice. ti,ab,kw
4. bassini. ti,ab,kw
5. mcvay. ti,ab,kw
6. stoppa.t ti,ab,kw
7. (laparoscop* NEAR25 herni*) ti,ab,kw
8. (tension-free NEAR25 herni*) ti,ab,kw
9. (conventional NEAR25 herni*). ti,ab,kw
10. (open NEAR25 herni*). ti,ab,kw
11. (darn NEAR25 herni*). ti,ab,kw
12. (mesh NEAR25 hern*). ti,ab,kw
13. (traditional NEAR25 herni*) ti,ab,kw
14. (plug NEAR25 herni*).t ti,ab,kw
15. (lichtenstein NEAR25 herni*).tw
16. 1 or 2 or 3 or 4 or 5 or 6 or 7 or 8 or 9 or 10 or 11 or 12 or 13 or 14 or 15

AND

Publication years Jan 2010- Dec2020

Notes on ENL:

Created separate ENL for Cochrane which was deduped and then copied into other ENL keyword: child, manually reviewed and deleted records

### DATABASE SEARCHED & TIME PERIOD COVERED

OVID MEDLINE & Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily - 1946 to March 26, 2020)

1. exp Hernia, Ventral/su [Surgery]
2. Abdominal Wall/su [Surgery]
3. (surgical mesh or open surgical technique* or open operative technique* or open suture repair* or mesh repair*).mp. [mp=title, abstract, original title, name of substance word, subject heading word, floating sub-heading word, keyword heading word, organism supplementary concept word, protocol supplementary concept word, rare disease supplementary concept word, unique identifier, synonyms]
4. 1 or 2 or 3
5. Hernia/
6. exp Hernia, Inguinal
7. Groin/
8. inguinal hernia or inguinal hernias or groin or groins
9. 5 or 6 or 7 or 8
10. 4 and 9

Limit – humans, 2010-2020, young adult, adult, middle age, middle aged, all aged

## VENTRAL HERNIA

### DATABASE SEARCHED & TIME PERIOD COVERED

PUBMED – 2010-2020

“Robotic Surgical Procedures”[Mesh] OR robotics[mh] OR robot-assisted OR robot*[tiab] OR robot*[ot]

AND

“surgical mesh” or “open surgical technique*” or “open operative technique*” or “open suture repair*” or “mesh repair*”

OR

“Abdominal Wall/surgery”[Mesh] OR “Hernia, Ventral/surgery”[Mesh]

AND

“ventral hernia” OR “incisional hernia”

OR

ventral hernia or incisional hernia

OR

“Hernia”[Mesh])

OR

“Hernia, Ventral"[Mesh]

AND

(limit) Humans

AND

(limit) adult

AND

“2010”[Date - Publication] : “3000”[Date - Publication]

### DATABASE SEARCHED & TIME PERIOD COVERED

EMBASE - 2010-2020

‘robot assisted surgery’/exp OR ‘robot assisted surgery’ OR ‘robot assisted’ OR robot*

AND

Abdominal wall hernia/exp OR incisional hernia/exp OR umbilical hernia/exp OR epigastric hernia/exp OR ‘incisional hernia’ OR ‘incisional hernias’ OR ‘ventral hernia’ OR ‘ventral hernias’ OR ‘umbilical hernia’ OR ‘umbilical hernias’ OR ‘epigastric hernia’ OR ‘epigastric hernias’

AND

Human/de

AND

adult/lim OR aged/lim OR very elderly/lim

AND

Publication years 2010-2020

### DATABASE SEARCHED & TIME PERIOD COVERED

COCHRANE – Jan 2010 – Dec 2020

Robotic assisted surgical procedures OR robotics OR (MESH descriptor) Robotic Surgical Procedures/exp OR (MESH descriptor)Robotics/exp

AND

Incisional hernia(Mesh descriptor)/exp OR Hernia, ventral(Mesh descriptor)/exp OR Hernia, umbilical (Mesh descriptor)/exp OR “incisional hernia” OR “Incisional hernias” OR “ventral hernia” OR “ventral hernias” OR “umbilical hernia” OR “umbilical hernias” OR “epigastric hernia” OR “epigastric hernias”:ti,ab,kw

AND

Publication years Jan 2010- Dec2020

NB: results reviewed for animal and children exclusion

### DATABASE SEARCHED & TIME PERIOD COVERED

OVID MEDLINE & Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily (1946 to March 26, 2020) –

1 exp Hernia, Ventral/su [Surgery]
2 Abdominal Wall/su [Surgery]
3 (surgical mesh or open surgical technique* or open operative technique* or open suture repair* or mesh repair*).mp. [mp=title, abstract, original title, name of substance word, subject heading word, floating sub-heading word, keyword heading word, organism supplementary concept word, protocol supplementary concept word, rare disease supplementary concept word, unique identifier, synonyms]
4 1 or 2 or 3
5 Hernia/
6 exp Hernia, Ventral/
  (ventral hernia or incisional hernia).mp. [mp=title, abstract, original title, name of substance word, subject heading word, floating sub-heading word, keyword heading word, organism supplementary concept word, protocol supplementary concept word, rare disease supplementary concept word, unique identifier, synonyms]
8 5 or 6 or 7
9 4 AND 8

AND

Humans (limit)

AND

Young adult OR adult Or middle age OR middle aged or all aged OR aged (limit)

AND

2010-1091 (limit)