# References

1 Population Reference Bureau. Fact Sheet: Aging in the United States. Report. Available at: https://www.prb.org/aging-unitedstates-fact-sheet/. Accessed December 6, 2018.
2 Ailes EC, Gilboa SM, Honein MA, . Estimated number of infants detected and missed by critical congenital heart defect screening. Pediatrics. 2015;135(6):1000–8.25963011
3 Centers for Disease Control and Prevention (CDC). National Center for Chronic Disease Prevention and Health Promotion. Multiple Chronic Conditions. Available at: https://www.cdc.gov/chronicdisease/about/multiple-chronic.htm. Accessed December 6, 2018.
4 Agency for Healthcare Research and Quality. The Distribution of the US Primary Care Workforce. Available at: https://www.ahrq.gov/research/findings/factsheets/primary/pcwork3/index.html. Accessed December 6, 2018.
5 Bodenheimer T, Pham HH. Primary care: current problems and proposed solutions. Health Aff (Millwood). 2010;29(5):799–805.20439864
6 Kullgren JT, McLaughlin CG, Mitra N, . Nonfinancial barriers and access to care for US adults. Health Serv Res. 2012;47(1 Pt 2):462–85.22092449
7 Douthit N, Kiv S, Dwolatzky T, . Exposing some important barriers to health care access in the rural USA. Public Health. 2015;129(6):611–20.26025176
8 Pitts SR, Carrier ER, Rich EC, . Where Americans get acute care: increasingly, it’s not at their doctor’s office. Health Aff (Millwood). 2010;29(9):1620–9.20820017
9 Agency for Healthcare Research and Quality. Healthcare Cost and Utilization Project (HCUP). Trends in Hospital Emergency Department Visits by Age and Payer, 2006-2015. Statistical Brief #238. March 2018. Available at: https://www.hcup-us.ahrq.gov/reports/statbriefs/sb238-Emergency-Department-Age-Payer-2006-2015.jsp. Accessed December 6,2018.
10 Galarraga JE, Pines JM. Costs of ED episodes of care in the United States. Am J Emerg Med. 2016;34(3):357–65.26763823
11 Gindi RM, Black LI, Cohen RA. Reasons for Emergency Room Use Among US Adults Aged 18-64: National Health Interview Survey, 2013 and 2014. Natl Health Stat Report. 2016(90):1–16.
12 O’Malley AS. After-hours access to primary care practices linked with lower emergency department use and less unmet medical need. Health Affairs. 2013;32(1):175–183.23242631
13 Critical Appraisal Skills Programme (CASP). CASP Qualitative Checklist. Available at: http://www.casp-uk.net/casp-tools-checklists. Accessed May 17, 2018.
14 Jue JS, Spector SA, Spector SA. Telemedicine broadening access to care for complex cases. J Surg Res. 2017;220:164–170.29180178
15 Mechanic OJ, Kimball AB. Telehealth Systems. StatPearls. Treasure Island (FL); 2018.
16 Shih J, Portnoy J. Tips for Seeing Patients via Telemedicine. Curr Allergy Asthma Rep. 2018;18(10):50.30112587
17 Saliba V, Legido-Quigley H, Hallik R, . Telemedicine across borders: a systematic review of factors that hinder or support implementation. Int J Med Inform. 2012;81(12):793–809.22975018
18 van Galen LS, Car J. Telephone consultations. BMJ. 2018;360:k1047.29599197
19 Reed M, Graetz I, Gordon N, . Patient-initiated e-mails to providers: associations with out-of-pocket visit costs, and impact on care-seeking and health. Am J Manag Care. 2015;21(12):e632–9.26760425
20 Brady M, Northstone K. Remote clinical decision-making: a clinician’s definition. Emergency Nurse. 2017;25(2):24–28.
21 Bunn F, Byrne G, Kendall S. Telephone consultation and triage: effects on health care use and patient satisfaction. Cochrane Database Syst Rev. 2004(4):Cd004180.15495083
22 Ismail SA, Gibbons DC, Gnani S. Reducing inappropriate accident and emergency department attendances: a systematic review of primary care service interventions. Br J Gen Pract. 2013;63(617):e813–20.24351497
23 Lake R, Georgiou A, Li J, . The quality, safety and governance of telephone triage and advice services - an overview of evidence from systematic reviews. BMC Health Serv Res. 2017;17(1):614.28854916
24 Ross J, Stevenson F, Lau R, . Factors that influence the implementation of e-health: a systematic review of systematic reviews (an update). Implement Sci. 2016;11(1):146.27782832
25 Newbould J, Abel G, Ball S, . Evaluation of telephone first approach to demand management in English general practice: Observational study. BMJ (Online). 2017;358.
26 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. PLoS Med. 2009;6(7):e1000097.19621072
27 Cochrane Effective Practice and Organisation of Care (EPOC). Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors Accessed May 17, 2018.
28 Evidence Partners Inc. DistillerAI website. Available at: https://www.evidencepartners.com/distiller-ai/. Accessed October 12, 2018.
29 Hong QN, Pluye P, Fàbregues S, . Mixed Methods Appraisal Tool (MMAT), version 2018. Registration of Copyright (#1148552), Canadian Intellectual Property Office, Industry Canada. Available at: http://mixedmethodsappraisaltoolpublic.pbworks.com/w/page/127425845/Download%20the%20MMAT. Accessed October 11, 2018.
30 Shea BJ, Bouter LM, Peterson J, . External validation of a measurement tool to assess systematic reviews (AMSTAR). PLoS One. 2007;2(12):e1350.18159233
31 Gale NK, Heath G, Cameron E, . Using the framework method for the analysis of qualitative data in multi-disciplinary health research. BMC Med Res Methodol. 2013;13:117.24047204
32 Thomas J, Harden A. Methods for the thematic synthesis of qualitative research in systematic reviews. BMC Med Res Methodol. 2008;8:45.18616818
33 Averill JB. Matrix analysis as a complementary analytic strategy in qualitative inquiry. Qual Health Res. 2002;12(6):855–66.12109729
34 Carrasqueiro S, Oliveira M, Encarnacao P. Evaluation of telephone triage and advice services: a systematic review on methods, metrics and results. Stud Health Technol Inform. 2011;169:407–11.21893782
35 Balshem H, Helfand M, Schunemann HJ, . GRADE guidelines: 3. Rating the quality of evidence. J Clin Epidemiol. 2011;64(4):401–6.21208779
36 Carrasqueiro S, Oliveira M, Encarnaço P. Evaluation of telephone triage and advice services: A systematic review on methods, metrics and results. 2011: 407–411.
37 Knowles E, O’Cathain A, Turner J, . Effect of a national urgent care telephone triage service on population perceptions of urgent care provision: controlled before and after study. BMJ Open. 2016;6(10):e011846.
38 Campbell JL, Fletcher E, Britten N, . Telephone triage for management of same-day consultation requests in general practice (the ESTEEM trial): a cluster-randomised controlled trial and cost-consequence analysis. Lancet. 2014;384(9957):1859–1868.25098487
39 Turner J, O’Cathain A, Knowles E, . Impact of the urgent care telephone service NHS 111 pilot sites: a controlled before and after study. BMJ Open. 2013;3(11):e003451.
40 Richards DA, Godfrey L, Tawfik J, . NHS Direct versus general practice based triage for same day appointments in primary care: cluster randomised controlled trial. BMJ. 2004;329(7469):774.15377574
41 Richards DA, Meakins J, Tawfik J, . Nurse telephone triage for same day appointments in general practice: multiple interrupted time series trial of effect on workload and costs. BMJ. 2002;325(7374):1214.12446539
42 McKinstry B, Walker J, Campbell C, . Telephone consultations to manage requests for same-day appointments: a randomised controlled trial in two practices. Br J Gen Pract. 2002;52(477):306–10.11942448
43 Lattimer V, George S, Thompson F, . Safety and effectiveness of nurse telephone consultation in out of hours primary care: randomised controlled trial. The South Wiltshire Out of Hours Project (SWOOP) Group. BMJ. 1998;317(7165):1054–9.9774295
44 Cragg DK, McKinley RK, Roland MO, . Comparison of out of hours care provided by patients’ own general practitioners and commercial deputising services: a randomised controlled trial. I: The process of care. BMJ. 1997;314(7075):187–9.9022434
45 Munro J, Nicholl J, O’Cathain A, . Impact of NHS Direct on demand for immediate care: Observational study. British Medical Journal: BMJ. 2000;321(7254):150–153.10894694
46 Kreuter MW, McQueen A, Boyum S, . Unmet basic needs and health intervention effectiveness in low-income populations. Prev Med. 2016;91:70–75.27496395
47 Buja A, Toffanin R, Rigon S, . Determinants of out-of-hours service users’ potentially inappropriate referral or non-referral to an emergency department: a retrospective cohort study in a local health authority, Veneto Region, Italy. BMJ Open. 2016;6(8):e011526.
48 Nyamtema A, Mwakatundu N, Dominico S, . Introducing eHealth strategies to enhance maternal and perinatal health care in rural Tanzania. Matern Health Neonatol Perinatol. 2017;3:3.28116114
49 Thomson GA, Fernando DJ, Bushby P, . A comprehensive e-education engine for a virtual diabetes centre. J Telemed Telecare. 2006;12: Suppl 1:48–50.16884579
50 Olden M, Wyka K, Cukor J, . Pilot Study of a Telehealth-Delivered Medication-Augmented Exposure Therapy Protocol for PTSD. J Nerv Ment Dis. 2017;205(2):154–160.27441461
51 Wang TT, Li JM, Zhu CR, . Assessment of Utilization and Cost-Effectiveness of Telemedicine Program in Western Regions of China: A 12-Year Study of 249 Hospitals Across 112 Cities. Telemed J E Health. 2016;22(11):909–920.27314300
52 Grustam AS, Severens JL, Van Nijnatten J, . Cost-effectiveness of telehealth interventions for chronic heart failure patients: A literature review. Int J Technol Assess Health Care. 2014;30(1):59–68.24495581
53 Raymond M, Harrison MC. The structured communication tool SBAR (Situation, Background, Assessment and Recommendation) improves communication in neonatology. South African Medical Journal. 2014;104(12):850–852.26042265
54 McKinley RK, Manku-Scott T, Hastings AM, . Reliability and validity of a new measure of patient satisfaction with out of hours primary medical care in the United Kingdom: development of a patient questionnaire. BMJ. 1997;314(7075):193–8.9022436
55 Holly J, Bledsoe J, Black K, . Prospective evaluation of an ED observation unit protocol for trauma activation patients. Am J Emerg Med. 2012;30(8):1402–1406.22205002
56 Mollerup A, Harboe G, Johansen JD. User evaluation of patient counselling, combining nurse consultation and eHealth in hand eczema. Contact Dermatitis. 2016;74(4):205–16.26822623
57 De Rosa M, Rinaldi E, Ortali M, . Virtual Consultation System To Enable Rare Diseases Diagnosis. Value Health. 2015;18(7):A366.
58 Lear SA, MacKinnon D, Farias-Godoy A, . Rapid access to cardiology expertise: an innovative program to provide telephone support for family physicians. Healthc Q. 2010;13(4):56–60.24953810
59 Joschko J, Liddy C, Moroz I, . Just a click away: Exploring patients’ perspectives on receiving care through the Champlain BASE™ eConsult service. Fam Pract. 2018;35(1):93–98.28968806
60 Howie JG, Heaney DJ, Maxwell M. Measuring quality in general practice. Pilot study of a needs, process and outcome measure. Occas Pap R Coll Gen Pract. 1997(75):i–xii, 1–32.9141884
61 Wahlberg AC, Bjorkman A. Expert in nursing care but sometimes disrespected - telenurses’ reflections on their work environment and nursing care. J Clin Nurs. 2018.
62 Eccles G, Edwards A. Evaluating a service improvement intervention in GP out-of-hours: impact of ‘expert triage model’. Qual Prim Care. 2015;23(1):9–17.
63 Foster J, Jessopp L, Dale J. Concerns and confidence of general practitioners in providing telephone consultations. Br J Gen Pract. 1999;49(439):111–3.10326262
64 Purc-Stephenson RJ, Thrasher C. Nurses’ experiences with telephone triage and advice: a meta-ethnography. J Adv Nurs. 2010;66(3):482–94.20423383
65 Röing M, Holmström IK. Malpractice claims in Swedish telenursing: lessons learned from interviews with telenurses and managers. Nurs Res. 2015;64(1):35–43.25502059
66 Blank L, Coster J, O’Cathain A, . The appropriateness of, and compliance with, telephone triage decisions: a systematic review and narrative synthesis. J Adv Nurs. 2012;68(12):2610–21.22676805
67 Edwards B. Seeing is believing-picture building: a key component of telephone triage. J Clin Nurs. 1998;7(1):51–7.9510708
68 Gamst-Jensen H, Lippert FK, Egerod I. Under-triage in telephone consultation is related to non-normative symptom description and interpersonal communication: a mixed methods study. Scand J Trauma Resusc Emerg Med. 2017;25(1):52.28506282
69 Pettinari CJ, Jessopp L. “Your ears become your eyes”: managing the absence of visibility in NHS Direct. J Adv Nurs. 2001;36(5):668–75.11737499
70 Timpka T, Arborelius E. The primary-care nurse’s dilemmas: a study of knowledge use and need during telephone consultations. J Adv Nurs. 1990;15(12):1457–65.2283459
71 Turnbull J, Prichard J, Pope C, . Risk work in NHS 111: the everyday work of managing risk in telephone assessment using a computer decision support system. Health, Risk & Society. 2017;19(3/4):189–208.
72 Pope C, Halford S, Turnbull J, . Using computer decision support systems in NHS emergency and urgent care: ethnographic study using normalisation process theory. BMC Health Serv Res. 2013;13:111.23522021
73 Tariq A, Westbrook J, Byrne M, . Applying a human factors approach to improve usability of a decision support system in tele-nursing. Collegian. 2017;24(3):227–236.
74 Richards SH, Pound P, Dickens A, . Exploring users’ experiences of accessing out-of-hours primary medical care services. Qual Saf Health Care. 2007;16(6):469–77.18055893
75 Holmström IK, Nokkoudenmäki MB, Zukancic S, . It is important that they care - older persons’ experiences of telephone advice nursing. J Clin Nurs. 2016;25(11-12):1644–1653.26961337
76 Holmström I, Höglund AT. The faceless encounter: Ethical dilemmas in telephone nursing. J Clin Nurs. 2007;16(10):1865–1871.17880475
77 Roberts A, Heaney D, Haddow G, . Implementation of a national, nurse-led telephone health service in Scotland: assessing the consequences for remote and rural localities. Rural Remote Health. 2009;9(2):1079.19368490
78 Turnbull J, Prichard J, Halford S, . Reconfiguring the emergency and urgent care workforce: mixed methods study of skills and the everyday work of non-clinical call-handlers in the NHS. J Health Serv Res Policy. 2012;17(4):233–40.23024183
79 O’Cathain A, Nicholl J, Sampson F, . Do different types of nurses give different triage decisions in NHS Direct? A mixed methods study. J Health Serv Res Policy. 2004;9(4):226–233.15509408
80 Derkx HP, Rethans JJ, Knottnerus JA, . Assessing communication skills of clinical call handlers working at an out-of-hours centre: development of the RICE rating scale. Br J Gen Pract. 2007;57(538):383–7.17504589
81 Banks J, Farr M, Salisbury C, . Use of an electronic consultation system in primary care: a qualitative interview study. Br J Gen Pract. 2018;68(666):e1–e8.29109115
82 Greatbatch D, Hanlon G, Goode J, . Telephone triage, expert systems and clinical expertise. Sociol Health Illn. 2005;27(6):802–30.16283900
83 Lopriore S, LeCouteur A, Ekberg S, . Delivering healthcare at a distance: Exploring the organisation of calls to a health helpline. Int J Med Inform. 2017;104:45–55.28599816
84 McKenzie R. Consumer awareness, satisfaction, motivation and perceived benefits from using an after-hours GP helpline - A mixed methods study. Aust Fam Physician. 2016;45(7):512–7.27610436
85 Baker R. Development of a questionnaire to assess patients’ satisfaction with consultations in general practice. Br J Gen Pract. 1990;40(341):487–90.2282225
86 Friedman BW, Mulvey L, Davitt M, . Predicting 7-day and 3-month functional outcomes after an ED visit for acute nontraumatic low back pain. Am J Emerg Med. 2012;30(9):1852–1859.22633712
87 Schunemann HJ, Cuello C, Akl EA, . GRADE guidelines: 18. How ROBINS-I and other tools to assess risk of bias in nonrandomized studies should be used to rate the certainty of a body of evidence. J Clin Epidemiol. 2019;111:105–114.29432858
88 Downes MJ, Mervin MC, Byrnes JM, . Telephone consultations for general practice: a systematic review. Syst Rev. 2017;6(1):128.28673333
89 Bunn F, Byrne G, Kendall S. The effects of telephone consultation and triage on healthcare use and patient satisfaction: a systematic review. Br J Gen Pract. 2005;55(521):956–61.16378566
90 Adam GP, Springs S, Trikalinos T, . Does information from ClinicalTrials.gov increase transparency and reduce bias? Results from a five-report case series. Syst Rev. 2018;7(1):59.29661214
91 Robinson KA, Saldanha IJ, McKoy NA. Development of a framework to identify research gaps from systematic reviews. J Clin Epidemiol. 2011;64(12):1325–30.21937195
92 Campbell JL, Fletcher E, Britten N, . The clinical effectiveness and cost-effectiveness of telephone triage for managing same-day consultation requests in general practice: a cluster randomised controlled trial comparing general practitioner-led and nurse-led management systems with usual care (the ESTEEM trial). Health Technol Assess. 2015;19(13):1–212, vii–viii.
93 Holt TA, Fletcher E, Warren F, . Telephone triage systems in UK general practice: analysis of consultation duration during the index day in a pragmatic randomised controlled trial. Br J Gen Pract. 2016;66(644):e214–8.26917660
94 Warren FC, Calitri R, Fletcher E, . Exploring demographic and lifestyle associations with patient experience following telephone triage by a primary care doctor or nurse: secondary analyses from a cluster randomised controlled trial. BMJ Qual Saf. 2015;24(9):572–82.
95 Calitri R, Warren FC, Wheeler B, . Distance from practice moderates the relationship between patient management involving nurse telephone triage consulting and patient satisfaction with care. Health Place. 2015;34:92–6.25982703
96 Murdoch J, Varley A, Fletcher E, . Implementing telephone triage in general practice: a process evaluation of a cluster randomised controlled trial. BMC Fam Pract. 2015;16:47.25887747
97 Varley A, Warren FC, Richards SH, . The effect of nurses’ preparedness and nurse practitioner status on triage call management in primary care: A secondary analysis of cross-sectional data from the ESTEEM trial. Int J Nurs Stud. 2016;58:12–20.27087294
98 Holt TA, Fletcher E, Warren F, . Telephone triage systems in UK general practice: Analysis of consultation duration during the index day in a pragmatic randomised controlled trial. Br J Gen Pract. 2016;66(644):e214–e218.26917660
99 Anonymous. Same-day GP and nurse-led telephone triage v usual care. Primary Health Care. 2014;24(8):15–15.
100 Mayor S. Primary care telephone triage does not reduce workload, study finds. BMJ: British Medical Journal. 2014;349(7970):2–2.
101 McKinley RK, Cragg DK, Hastings AM, . Comparison of out of hours care provided by patients’ own general practitioners and commercial deputising services: a randomised controlled trial. II: The outcome of care. BMJ. 1997;314(7075):190–3.9022435
102 Lattimer V, Sassi F, George S, . Cost analysis of nurse telephone consultation in out of hours primary care: evidence from a randomised controlled trial. BMJ. 2000;320(7241):1053–7.10764368
103 Savings outweigh costs of nurse telephone consultation in out of hours primary care. BMJ. 2000;320(7241):E.
104 Southard EP, Neufeld JD, Laws S. Telemental health evaluations enhance access and efficiency in a critical access hospital emergency department. Telemed J E Health. 2014;20(7):664–8.24811858
105 O’Cathain A, Knowles E, Turner J, . Acceptability of NHS 111 the telephone service for urgent health care: cross sectional postal survey of users’ views. Fam Pract. 2014;31(2):193–200.24334420
106 Richards DA, Meakins J, Godfrey L, . Survey of the impact of nurse telephone triange on general practitioner activity. Br J Gen Pract. 2004;54(500):207–210.15006127
107 Ernesater A, Holmstrom I, Engstrom M. Telenurses’ experiences of working with computerized decision support: supporting, inhibiting and quality improving. J Adv Nurs. 2009;65(5):1074–83.19399984
108 O’Cathain A, Sampson FC, Munro JF, . Nurses’ views of using computerized decision support software in NHS Direct. J Adv Nurs. 2004;45(3):280–6.14720245
109 Turnbull J, Pope C, Rowsell A, . Health Services and Delivery Research: The work, workforce, technology and organisational implications of the ‘111’ single point of access telephone number for urgent (non-emergency) care: a mixed-methods case study. 2014.
110 Bjorkman A, Engstrom M, Olsson A, . Identified obstacles and prerequisites in telenurses’ work environment - a modified Delphi study. BMC Health Serv Res. 2017;17(1):357.28521743
111 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184