# Acknowledgments

This topic was developed in response to a nomination by Jennifer MacDonald, MD, Office of Connected Care for the purpose of developing an enterprise master plan for clinical contact center optimization. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the Technical Expert Panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Chad Kessler, MD, National Program Director, Emergency Medicine, Veterans Health Administration for his help, Eric Monson, PhD, for his help with data visualization and the following individuals for their contributions to this project:

## Operational Partner

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Jennifer MacDonald, MD
  Clinical Lead
  Office of Connected Care

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Becky Yano, PhD, MSPH
  Director, VA HSR&D Center for the Study of Healthcare Innovation, Implementation & Policy
  Deputy Associate Chief of Staff (ACOS) for Health Services Research
  VA Greater Los Angeles Healthcare System
- Peter Kaboli, MD, MS
  Chief of Medicine
  Iowa City VA Health Care System
- Danielle Rose PhD, MPH
  Core Investigator
  VA Greater Los Angeles Healthcare System

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or nonfinancial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.