# Methods

We followed a standard protocol for this review. Each step was pilot-tested to train and calibrate study investigators. The PROSPERO registration number is CRD42019112262. We adhered to the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines.^26^

## Topic Development

This topic was proposed by a multi-program office, multidisciplinary governance structure led by the Office of Connected Care and Office of Nursing Services to develop an enterprise master plan for clinical contact center optimization. Additionally, this VHA structure will become part of a larger department-level governance structure overseeing all contact center modernization, including administrative efforts. This information will be relevant to the VHA, Veterans Benefit Association, and the National Cemetery Association stakeholders as enterprise-level technology, staffing, and other decisions are to be made.

### Key Questions

The Key Questions (KQs) for this report were:

KQ 1:

A. For adults, what are the effects of remote triage on health care utilization, case resolution, patient safety, patient satisfaction, and cost?
B. What is the impact of remote triage by different modalities (eg, telephone, video, web, short message service [SMS])?

KQ 2: What are the identified best practices that impact the planning, execution, and evaluation of remote triage for adults seeking clinical care advice in a large-scale health system such as the VA?

KQ 3: What are the types of outcomes used to assess the impact of remote triage?

## Search Strategy

In collaboration with an expert reference librarian, we conducted 2 different primary literature searches (one for KQs 1 and 3 and a separate search for KQ 2) from inception through July 27, 2018, of MEDLINE^®^ (via PubMed^®^), EMBASE, and CINAHL. We used a combination of MeSH keywords and selected free-text terms (eg, triage, telenurses, helpline) to search titles and abstracts (Appendix A). We also conducted hand-searches of references from selected high-quality systematic reviews and exemplar studies identified during the topic development process and identified by our stakeholders.

Our search strategy was informed by the Cochrane Effective Practice and Organization of Care (EPOC) Group.^27^ EPOC criteria were developed to capture both randomized and nonrandomized study designs. All citations were imported into 2 electronic databases (for referencing, EndNote^®^, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR; Evidence Partners Inc., Manotick, ON, Canada).

## Study Selection

We used the artificial intelligence (AI) technology developed as part of the DistillerSR software, called DistillerAI, to assist with screening abstracts. Using prespecified inclusion/exclusion criteria (Table 1), the titles and abstracts of a subset of articles (n=100 for KQ1 and n=150 for KQ 2) identified through our primary search were classified independently by 2 senior investigators for relevance to the KQs. After resolving disagreements between the investigators, this set of included and excluded articles was used to train DistillerAI.^28^

We used DistillerAI to screen citations using different approaches for KQs 1 and 3 and KQ 2. For both approaches, the titles and abstracts were assigned a probability of relevance to the study questions by DistillerAI using both a Naive Bayes classifier and Support Vector Machine classifier. For literature associated with KQ 1, all citations with a relevance probability score of 1 underwent full-text review by 2 investigators. All citations classified as lower probability of inclusion were screened by 1 investigator. The citations that were unclassified by DistillerAI underwent screening by 2 investigators. For literature associated with KQ 2, all titles and abstracts were reviewed by DistillerAI. Citations with ≥50% probability of inclusion advanced to the full-text review stage. Citations classified by DistillerAI as excluded (<51% probability) were reviewed by 1 investigator.

Citations included by an investigator or DistillerAI based on the title and abstract underwent full-text screening. At the full-text screening stage, 2 independent investigators agreed on a final inclusion/exclusion decision. All articles meeting eligibility criteria were included for data abstraction. The outcomes used to assess remote triage (KQ 3) used publications identified in KQ 1.

Table 1 Eligibility Criteria

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population | KQ 1/KQ 3, KQ 2: Adults (≥18 years of age) and their families and caregivers; KQ 2: Stakeholders involved in the uptake, management, and implementation of remote triage services (eg, nurses, administrators, organizational leadership) | Inpatient populations; Populations in residential facilities that provide regular medical care (eg, long-term care, nursing home)
Intervention | Remote triage services, defined as services pertaining to the initial assessment and management of acute, undifferentiated, or unscheduled care initiated by a patient or family member from a distance that is focused on a clinical care issue | Interventions defined primarily as:; - Telemonitoring; - Health coaching; - In-person presentations (eg, walkins); - Counseling; - Longitudinal care management (ie, more than 1 contact for an ongoing condition, routine follow-up); - Provider-to-provider communications or consultations beyond the initial transfer of information from a patient-initiated contact; - Urgent mental health crisis lines (eg, suicide hotlines) or emergency medical services (eg, 911); Interventions related only to the use of remote triage for the following:; - Specific population or demographic (eg, pediatric only, ethnic minority); - Specific condition (eg, depression) medical specialty (eg, asthma) or ongoing or chronic conditions (eg, diabetes); - Technical assessments not related to patient or health care outcomes; - General health education
Comparator | KQ 1:; - Usual care/standard of care, waitlist control; - Other active comparator (eg, in-person care; KQ 2, KQ 3: No comparator required | KQ 1: No controls; KQ 2, KQ 3: No exclusion criteria
Outcome^a^ | KQ 1: Patient satisfaction, health care utilization, case resolution, cost to deliver or cost per member, and patient safety; KQ 2: Best practices for remote triage system (eg, insights into personnel, processes, and technologies needed to establish a remote triage; implications for what works well and what does not in conducting remote triage); KQ 3: Outcomes used to assess remote triage from publications identified in KQ 1 | Any outcomes not listed
Setting | Outpatient general medical settings (eg, family medicine, general internal medicine, integrative medicine, urgent care, emergency departments); Community settings; KQ 2: Large health care systems | Intervention delivered primarily in hospital inpatient setting; Mass casualty event; Specialty medical settings for management of chronic medical conditions
Study design | KQ 1: EPOC criteria studies^a^ that have prospective data collection:; - Randomized trials; - Nonrandomized trials; - Controlled before-after studies; - Interrupted time-series studies or repeated measures studies; KQ 2, KQ 3:; - Above KQ study designs, and the following designs if they address best practices in implementing remote triage services:; - Qualitative studies; - Systematic reviews; - Organizational case studies | KQ 1:; - Self-described pilot studies without adequate power to assess impact of intervention on outcomes.; - Studies of small sample sizes (n<100); - Not a clinical study (eg, editorial, nonsystematic review, letter to the editor); - Uncontrolled clinical study; - Qualitative studies; - Prospective and retrospective observational studies; - Clinical guidelines; - Measurement or validation studies; KQ 2, KQ 3: Studies that do not include exploration of best practices in remote triage
Language | English | Non-English
Countries | OECD^b^ | Non-OECD
Years | 1990 forward | None
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

a See Cochrane EPOC criteria for definitions and details.^27^

b OECD = Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

## Data Abstraction

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. Data elements included descriptors to assess applicability, quality elements, intervention/exposure details, and outcomes. When we used an existing high-quality systematic review, we spot-checked critical data from the primary literature as needed to confirm accurate abstraction/interpretation by the authors of the review.

Key characteristics abstracted were patient descriptors (eg, age, sex, race, Veteran status), intervention characteristics (eg, interventionist, delivery modality, key intervention components), comparator, and outcomes, as described previously. For studies relevant to KQ 2, we abstracted best practices (ie, description of themes or factors that relate to the planning, execution, evaluation, people, process and technology) for the implementation of remote triage services. For KQ 3 we abstracted the measures and metrics used to evaluate remote triage systems. Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. Key features relevant to applicability included the match between the sample and target populations (eg, age, Veteran status). For details of intervention characteristics and study characteristics, see Appendices B and C. Appendix D lists excluded studies and the reason for exclusion.

## Quality Assessment

Quality assessment was done by the investigator abstracting or evaluating the included article and was over-read by a second, highly experienced investigator. Disagreements were resolved by consensus between the 2 investigators or, when needed, by arbitration by a third investigator.

For all KQs, we used the Cochrane EPOC risk of bias (ROB) tools, which are applicable to randomized studies, nonrandomized studies, controlled before-after studies, and interrupted time-series studies.^27^ These criteria are adequacy of randomization and allocation concealment; comparability of groups at baseline; blinding; completeness of follow-up and differential loss to follow-up; whether incomplete data were addressed appropriately; protection against contamination; and selective outcomes reporting. The criteria specific to interrupted time-series studies include intervention independence from other changes; prespecified shape of intervention effect; intervention unlikely to affect data collection; knowledge of allocated interventions adequately prevented; incomplete outcome data addressed; absence of selective outcome reporting; and absence of other risks of bias. We assigned a summary ROB score (low, unclear, high) to individual studies.

Summary ROB ratings are defined as follows:

- Low ROB: Bias, if present, is unlikely to alter the results seriously.
- Unclear ROB: A risk of bias that raises some doubts about the results.
- High ROB: Bias may alter the results seriously.

For KQ 2 qualitative studies, we used the 5 items specific to qualitative studies from the Mixed Methods Appraisal Tool (MMAT).^29^ These criteria address the appropriateness of the qualitative approach; the adequacy of data collection methods; findings adequately derived from the data; results sufficiency supported by the data; coherence between qualitative data sources, collection, analysis and interpretation. The MMAT rates each item “Yes,” “No,” or “Can’t tell”; there is no summary rating.

For KQ 2 systematic review studies, we adapted the AMSTAR critical appraisal tool.^30^ These criteria address a priori design; specified eligibility criteria; appropriateness of eligibility restrictions; comprehensive literature search strategy; comprehensive search terms; restrictions on strategy appropriate; selection bias; duplicate study selection and data abstraction; characteristics of the included studies provided; quality of included studies assessed; quality of included studies appropriately addressed in conclusions; methods used to combine findings appropriate; addressed between-study variation; publication bias assessed; conclusions supported by data; and conflict of interest stated. We assigned a summary ROB score (good, fair, poor) to individual studies.

## Data Synthesis

### KQ 1 Effects of Remote Triage

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator. We then determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects. For meta-analyses, feasibility depends on the volume of relevant literature, conceptual homogeneity of the studies, and completeness of results reporting. We were unable to aggregate outcomes because of heterogeneity of outcome reporting, time points, and methodology. Thus, we analyzed the data narratively. We gave more weight to the evidence from higher quality studies (eg, randomized designs, low ROB studies) with more precise estimates of effect. When possible, we present forest plots of the point estimates of individual studies, grouped by the overall type of comparison drawn in each study. Narrative synthesis focused on documenting and identifying patterns in results of the interventions across conditions and outcome categories. We analyzed potential reasons for inconsistency in effects across studies by evaluating differences in the study population, triage system, comparator, and outcome definitions.

### KQ 2 Best Practices for Remote Triage

For the KQ 2 analysis, we set up a team of 3 co-investigators (JMG, AAL, SR) who had experience in qualitative methodology. The qualitative team analyzed the abstracted data from the KQ 2 studies using thematic synthesis and the framework method.^31,32^ Using the KQ 2 question as a guide, they created an a priori framework developed in collaboration with our stakeholders and Technical Expert Panel. This framework included 3 phases of best practice: planning, execution, and evaluation; and 3 aspects of best practice: people, processes, and technology. All abstracted findings were first categorized into phase (ie, planning, execution, and evaluation), and then within each phase were categorized by aspect (ie, people, processes, and technology) Abstracted data could be categorized into more than 1 phase and aspect; additionally, text sections could be categorized into multiple relevant phases and/or aspects. For instance, an abstracted piece of text could be categorized as execution phase and both as person and process aspects.

The qualitative team first abstracted data into a Microsoft Excel spreadsheet for data cleaning and organization. Then, the team used NVivo software to support first- and second-level coding and analysis (QSR International Pty Ltd, Version 12, 2018). Rigor and validity were established during data cleaning and organization as the qualitative team over-read 100% of abstracted data in Excel. After the data were coded, a coder external to the project over-read 100% of the coded text in NVivo to assess validity of the coding schema. When a disagreement in abstracted or coded text arose, the team discussed the text as a group and came to a consensus at their weekly meeting. This over-reading process confirmed the validity of the interpretations.

After the data were independently coded, over-read, and discussed among the 3 qualitative researchers, they conducted a thematic synthesis by identifying and grouping related codes across each phase (eg, planning, execution, and evaluation) and aspect (people, processes, and technology). The creation and identification of codes and themes was iterative. To ensure rigor and validity of these findings, the team independently coded and developed themes and then discussed theme development and identification until they reached agreement. As a data-reduction technique, we used matrix analysis and categorized themes in each phase of best practice to compare and contrast findings.^33^

### KQ 3 Assessment of Remote Triage

For the studies that met inclusion criteria for KQ 1, we categorized the types of metrics used to assess the impact of remote triage. We adapted 6 categories developed by Carrasqueiro et al^34^: (1) enhanced access to care; (2) change in rates or trends of services use or change in professionals’ workload; (3) adverse events (deaths, emergency department attendance, hospital admissions) and delayed care; (4) clinical outcomes after triage; (5) patient satisfaction measured via Likert scales; and (6) savings from avoided services use and triage costs.

## Rating the Body of Evidence

The certainty of evidence (COE) for KQ 1 was assessed using the Grading of Recommendations Assessment, Development and Evaluation (GRADE)^35^ approach. We limited GRADE ratings to those outcomes identified by the stakeholder and Technical Expert Panel as critical to decision-making, specifically health care utilization, patient safety, and patient satisfaction. In brief, this approach requires assessment of 4 domains: risk of bias (ROB), consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by 2 investigators (AMG, JMG) as high, moderate, low, or very low COE.

## Peer Review

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses is in Appendix E.