# Evidence Report

## Introduction

The US health care system currently faces several challenges, including caring for an increasing elderly population,^1^ large numbers of patients with multiple chronic conditions,^2,3^ and an uneven distribution of primary care providers across the country.^4^ The full appointment schedules of many primary care physicians compound this workforce shortage, making it challenging for many patients to access acute and chronic care within a primary care setting.^5^ Additionally, many patients experience barriers to receiving care, which span financial and nonfinancial burdens.^6^ In rural areas, for example, patients may face not only a decreased number of providers, but also challenges with internet access and public transportation for arranging and attending appointments.^7^

Such access challenges may lead people to seek acute or chronic care in settings such as emergency departments (EDs) when their needs could have likely been addressed in a primary care setting. Increasingly, acute care visits take place outside of the primary care setting.^8^ The number of annual ED visits has been growing,^9^ and, in 2010 the United States spent $328.1 billion on ED care.^10^ In 2016 Gindi et al^11^ found that 12% of patients visited the ED because it was not during their primary care office hours and another 7% visited the ED because of an inability to visit another provider. As might be expected, patients who have access to after-hours care at their usual primary care practice have lower rates of higher level care utilization.^12^ One way of providing patient access to the appropriate level of care is through remote technology. The use of technology to reach across distances to deliver health care is known as telemedicine and has the potential to impact society, health care systems, and individual patients and family.^13^ In certain settings, the use of telemedicine has been shown to reduce both time and financial costs, while 86% of patients in a large health care systems noted increased access to care.^14^

Telemedicine can be delivered via a synchronous format (“real-time” communication between patient and provider), asynchronous format (“one-way” communication to either patient or provider), or remote monitoring.^15^ Specific technologies to deliver telemedicine may include email, internet-based, and remote store-and-forward platforms,^16^ as well as video conferencing and satellite-based technologies,^17^ among others. These technologies may also be used in multiple ways: telephone interactions, for example, can be used to address acute, chronic, and preventive care issues.^18^ Similarly, patients also can use secure email as a means of first contact to address a wide variety of concerns such as acute conditions, test results, medication, chronic care, and requests for referrals.^19^

Remote decision-making is defined as making clinical decisions in the absence of a face-to-face encounter.^20^ Remote decision-making can overcome barriers such as demand for in-person clinical services. In a 2004 Cochrane systematic review, Bunn et al^21^ determined telephone consultation with patients and triage decreased urgent visits for medical and surgical patients, but further research is needed to determine if this represents an absolute decrease in appointment utilization versus a deferral in care to a later time. Another, more recent systematic review found limited information available to broadly assess the impact of remote triage on clinical outcomes and cost with mixed results related to the impact on emergency department use.^22^ These latter findings are similar to findings of another study that determined additional information is needed related to the outcomes of telephone triage and advice lines.^23^

The implementation of any technology-based system is complex and requires the evaluation of multiple factors within an organization as part of the planning process. General factors that would affect deploying telemedicine strategies include the specific clinical and population contexts, cultural influences within the patient population, the ability to sustain the process, and legal considerations around medical decision-making and disposition.^17^ Another study identified specific issues requiring consideration for execution, including the system’s adaptability to fit local needs, the complexity of both the system and the intervention, cost, external forces such as incentives and mandates, internal forces such as supportive resources, and top-down engagement.^24^ For example, primary care providers (PCPs) in the United Kingdom have implemented a practice of requiring phone consultations with patients requesting same-day appointments to assess whether the condition could be addressed without a face-to-face visit. This practice led to a decrease in face-to-face acute visits, although it increased PCP workload to manage the triage.^25^

The current review was requested by the VA Office of Connected Care, which partners with the Office of Nursing Services to develop an enterprise master plan for clinical contact center optimization. The review will be used to identify the current evidence base and its quality surrounding outcomes related to remote triage services for acute care needs across multiple platforms. Furthermore, it will identify best practices and potential barriers in the further adoption of these telemedicine platforms within the Veterans Health Administration (VHA) system. Prior systematic reviews on this topic are inadequate for the needs of these stakeholders because they do not include recent important studies nor consider geographic and integration issues in a system the size of the VHA. Additionally, we seek to determine whether data exist to adequately determine performance of these remote triage systems for continuous measurement and improvement.