# APPENDIX F Glossary

For full study citations in this appendix, please refer to the report’s main reference list.

Term: Definition
After-hours: Hours of operation outside of regular business hours, typically between 5:00pm and 7:00am, weekends, and business holidays; also referred to as out-of-hours.
Best practices: Processes that are accepted or proven to be most effective in optimizing positive outcomes.
Case resolution: When a remote triage telephone call is managed on the first contact without triage to other services, or when a caller is connected with the appropriate individual with only 1 call transfer.
Certainty of evidence (COE): We assessed COE using the Grading of Recommendations Assessment, Development and Evaluation (GRADE) approach^111^ for 4 domains:
  Domain | Rating | How Assessed
  Risk of bias | Low; Unclear; High | Assessed primarily through study design and aggregate study quality
  Consistency | Not serious inconsistency; Serious inconsistency; Very serious inconsistency | Assessed primarily through whether effect sizes are generally on the same side of “no effect,” the overall range of effect sizes, and statistical measures of heterogeneity
  Directness | Not indirect; Serious indirectness; Very serious indirectness | Assessed by whether the evidence involves direct comparisons or indirect comparisons through use of surrogate outcomes or use of separate bodies of evidence
  Precision | Not serious imprecision; Serious imprecision; Very serious imprecision | Based primarily on the size of the confidence intervals of effect estimates, the optimal information size and considerations of whether the confidence interval crossed a clinical decision threshold
  Summary COE ratings for a body of evidence:
  - High—High confidence that the true effect lies close to that of the estimate of the effect.
  - Moderate—Moderate confidence in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
  - Low—Limited confidence in the effect estimate. The true effect may be substantially different from the estimate of the effect.
  - Very low—Very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.
  - Insufficient—Impossible or imprudent to rate. In these situations, a rating of insufficient is assigned.
Commercial deputizing service: A service provided by a commercial external agency that has been delegated to cover care for general practitioners.
General practitioner (GP): A general physician who provides care to a broad population without regard to specific medical specialty. Typically, GPs train and practice in the UK and similar health systems.
Objective outcomes (ie, non–patient-reported outcomes): Measures that are not subject to a large degree of individual interpretation and are likely to be reliably measured across patients in a study, by different health care providers, and over time.
Patient-reported outcomes: Outcomes that are directly reported by the patient without interpretation of the patient’s response by a clinician or anyone else and pertains to the patient’s health, quality of life, or functional status associated with health care or treatment.
Risk of bias (ROB): An assessment of study quality. We used the following guidance in this report.
  (1) For all KQs, we used the Cochrane EPOC ROB tool, which is applicable to randomized and nonrandomized studies^27^:
  - Randomization and allocation concealment
  - Comparability of groups at baseline
  - Blinded outcomes assessment
  - Completeness of follow-up and differential loss to follow-up
  - Whether incomplete data were addressed appropriately
  - Protection against contamination
  - Selective outcomes reporting
  - Intervention independent from other changes (specific to interrupted time series)
  - Intervention pre-specified (specific to interrupted time series)
  - Intervention affect on data collection (specific to interrupted time series)
  Summary ROB ratings for a study:
  - Low ROB—Bias, if present, is unlikely to alter the results seriously
  - Unclear ROB—Bias that raises some doubts about the results
  - High ROB—Bias that may alter the results seriously
  (2) For KQ 2, we used the Mixed Methods Appraisal Tool (MMAT) 5-item criteria to evaluate the ROB for qualitative study designs^29^
  - Appropriate qualitative approach
  - Adequacy of data collection methods
  - Findings derived from the data
  - Results supported by the data
    - Coherence between qualitative data sources, collection, analysis and interpretation
  No summary ROB was possible for the MMAT.
  (3) For KQ 2, we used the AMSTAR critical appraisal tool to evaluate eligible systematic review studies^30^:
  - A priori design
  - Specified eligibility criteria
  - Appropriateness of eligibility restrictions
  - Comprehensive literature search strategy and search terms
  - Appropriate search strategy restrictions
  - Selection bias avoided
  - Duplicate study selection and data abstraction
  - Characteristics of included studies reported
  - Quality of included studies assessed
  - Conclusions supported by data
  - Conflict of interest stated
  Summary ROB ratings for a study:
  - Good—if present, none of the limitations are thought to decrease the validity of the conclusions
  - Fair—some uncertainty about the validity of the conclusions
  - Poor—serious uncertainty about the validity of the conclusions
Standardized mean difference (SMD): The difference in outcomes between the intervention and comparator, divided by the pooled standard deviation.