# APPENDIX E Peer Review Comments and Response Table

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Executive Summary should be heavily revised as program partners are unlikely to have time to read the detailed report (which is well written, well organized, insightful, and solid). The Executive Summary has many typos (words that need to be pluralized, missing words, etc.) and does a somewhat poor job of melting down the main report’s solid introduction to the point where I was puzzled by the points being made. (e.g., limited provider time, transportation and financial burden are NOT the only other barriers to receiving timely primary care). | Thank you, we have addressed the typos and refined the background information pulled from our main report introduction into the Executive Summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | The purpose of triage systems is not clearly enough made in the executive summary either, though in the main report it is well explicated and logical. Technology-based systems are not explained and high-demand for services is not the crux (paragraph 1). | We have expanded on the context for this project in the Executive Summary introduction.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | The executive summary is also not anchored in VA relevance other than a program office partner request - instead, this report is extremely important to the next steps of the Office of Connected Care, which itself is linked to MISSION Act and EHRM initiatives. | We have added a description of the VA-specific policy context in the executive summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | The key takeaway points in the summary are lost in the mix of narrative and should be brought forward to make it easier for partners to understand. For example, page 4 top lines: “Evidence suggested that local, practice-based phone triage services have higher case resolution outcomes and refer fewer patients to emergency or primary care services compared with regional/national telephone-based remote triage." This is HUGE! | Thank you, we have created bullet points to highlight the key points in the Executive Summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Same thing with moderate quality of evidence for not managing to decrease ED use (double negatives in sentences around lines 23-26 needs help - I had to read them a couple of times to understand what was being said). | Thank you for this comment. We have addressed this sentence structure in the final draft.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | And there is no context for the statement - OCC is hoping/assuming/trusting that the VA telephone triage work is going to reduce PC and ED visit rates. It is implied but never stated clearly. If there’s not a lot of evidence this is the case, that’s again HUGE. | Thank you. We have added more context and clarity to this finding in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | I don’t understand the last sentence on page 4 lines 26-27 either and does not seem to be of the same value as the other findings included in the executive summary. | We have addressed the wording of this statement in the final report in order to highlight that there is limited high-quality evidence that reported on these prioritized outcomes (n=3).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | In the certainty of evidence table, which is very helpful, there is a missing “to" in line 38 (0.34 fewer to 2.5 more). And there is no information to anchor readers on what ROB means, so recommend the table include not just an explanation of ROB = risk of bias but at least a broad-stroke notion of what fits in that so program partners can better understand why it is a problem/issue. Remember they may never read the report itself, so the executive summary is perhaps the most important part of this report and has to be able to stand on its own. | Thank you for this comment. We have addressed the typo in the certainty of evidence table. We have also added further information about the risk of bias rating to the executive summary under the data abstraction and quality assessment heading.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Page 5, line 13, we need to know the 11 themes. Operations partners are not going to have time to go through the rest of the report to find them (or at least give them a cross-reference to make it easy or better yet add a table here to go through them like the confidence table). | A table describing the KQ 2 11 themes has been added to the executive summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Do not understand the statement on page 5 line 52 around “protocols that undermine nurse clinical judgment.” | Thank you, we have significantly revised the summary of KQ 2 and this sentence no longer appears in the Executive Summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Recommendations in the executive summary also need to be bolded or underlined or something to help them come forward (e.g., page 5, lines 43-49) so there is more of a roadmap feel here for adding value to partners trying to extract some key knowledge from the report. | We have added a structure to the KQ 2 section of the Executive Summary to highlight findings.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Page 6 reference to this as a “meticulous" review was a little off putting - your operational partners will not know either way, and while it is my sense that the ESP team did an extraordinary job here, this self pat on the back in a summary that did not make it easy to grasp takeaways did not add value. | Thank you for your comment; we have addressed this issue in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | In the Key Findings section, I really wanted to see more about the hypothesized impacts up front so contextualize what the team found (noted partly above). What does telephone triage aim to accomplish? That needs to be up front so that the frame is set for readers. | We have added more context to the Key Findings section of the discussion to ground our results.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Under applicability, page 6 line 57, should be findings (not finding) - there are a lot of places where the grammar needs some help. | Thank you; we have addressed this typo in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | I suspect given the magnitude of the tasks underlying this report that the executive summary was the last piece added, so I get that, and applaud the ESP team for an exceptional heavy lift on the report that may have contributed to less time on the summary, but I would urge the team to rework the summary, tighten the frame (what triage systems are supposed to accomplish in theory/hope)/rationale for its conduct, tighten the language/writing, and ensure that the main messages are brought forward in a clearer way through formatting or other revisions. | Acknowledged. We have addressed this in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Under research gaps, line 7 make it delivery (not deliver). Too many of these to list them all here, so needs a word-by-word read/edit up front. | Thank you, we have addressed this and similar issues in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | In sum, exceptional report, solid writing of the main body of the report, anticipate that this report will have major impacts and contributions to practice and policy improvements, with the proviso that if partners really do only read the executive summary, it needs a major revision to cogently and clearly deliver its main messages/takeaways and to do the rest of the report justice | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Tremendous amount of work went into this. Very disappointing there was not more evidence to evaluate and give policymakers more information about the effectiveness of remote triage but no negative comments about the work. It’s a rigorous and comprehensive review of existing literature. | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Typos; Page 1, line 7. Do you “an uneven distribution of providers” | Thank you, this has been fixed in the final report.