# APPENDIX D Excluded Studies

## KQ 1 Excluded Studies

Exclusion reason Study | Not full publication | Not population of interest | Not eligible setting | Not eligible intervention | Not eligible design | Not eligible outcome
Albahri, 2018^1^ | | | | | X
Andrews, 2014^2^ | X
Anonymous, 1997^3^ | | X
Anonymous, 2015^4^ | X
Anonymous, 2015^5^ | X
Anonymous, 2015^6^ | X
Anonymous, 2014^7^ | X
Bearden, 2008^8^ | | | | | X
Bergmo, 2005^9^ | | | | X
Biermann, 2002^10^ | | | | X
Blank, 2012^11^ | X
Campbell, 2015^12^ | X
Carrasqueiro, 2011^13^ | | | | | X
Castro, 2014^14^ | | | | X
Chmiel, 2011^15^ | | | | | X
Cronin, 2017^16^ | | X
Dale, 2011^17^ | X
de Coster, 2010^18^ | | | | | X
Downes, 2017^19^ | | | | | X
Dunt, 2006^20^ | | | | | X
Dunt, 2007^21^ | | | | | X
Eccles, 2015^22^ | | | | | X
Eppes, 2012^23^ | | | X
Garratt, 2007^24^ | | | | | X
Godfrey, 2006^25^ | X
Gulacti, 2017^26^ | | | | X
Gulacti, 2017^27^ | | | | X
Hansen, 1998^28^ | | | | | X
Holroyd, 2007^29^ | | | | X
Howard, 2007^30^ | | | | | X
Howell, 2016^31^ | | X
Huber, 2011^32^ | | | | X
Huibers, 2011^33^ | | | | X
Huibers, 2012^34^ | | | | | X
Jackman, 1998^35^ | | X
Jones, 2018^36^ | | | | X
Katz, 2003^37^ | | | | | | X
Kim, 2013^38^ | | | | X
Klasner, 2006^39^ | | X
Knight, 2010^40^ | | X
Krumperman, 2015^41^ | | | | | X
Liedberg, 2016^42^ | | | X
Lin, 2005^43^ | | | | X
Mallett, 2014^44^ | | | | X
Manzo-Silberman, 2015^45^ | | | | X
Marsh, 2014^46^ | | | X
Mayor, 2014^47^ | | X
Melnyk, 2008^48^ | | X
Morrissey, 1997^49^ | | X
Murdoch,2015^50^ | | | | | X
Nagle, 1992^51^ | | | | | X
Navratil-Strawn, 2014^52^ | | | | | X
O’Keeffe, 2008^53^ | | | | X
O’Malley, 2013^54^ | | | | X
Ong, 2008^55^ | | | | | X
Philips, 2010^56^ | | | | X
Philips, 2012^57^ | | | X
Purc-Stephenson, 2012^58^ | | | | | X
Rahmqvist, 2011^59^ | | | | X
Richards, 2008^60^ | | | X
Roberts, 2007^61^ | X
Roberts, 2007^62^ | X
Roth, 2006^63^ | | | | X
Rouse, 2007^64^ | | X
Salk, 1998^65^ | | | | X
Shannon, 2006^66^ | | | | X
Shekelle, 1999^67^ | | X
Smits, 2012^68^ | | | | X
Smits, 2017^69^ | | X
Smitsa, 2016^70^ | | X
Somers, 1994^71^ | | X
Soulleihet, 2014^72^ | | | | X
Spaulding, 2012^73^ | | | | X
Stacey, 2014^74^ | | | | X
Stuart, 2000^75^ | | | | | X
Takala, 1997^76^ | | | | X
Thompson, 1999^77^ | | X
Turner, 2009^78^ | | | | X
Valsangkar, 2017^79^ | | | X
van Ierland, 2011^80^ | | | | X
Van Uden, 2005^81^ | | | | | X
Villarreal, 2017^82^ | | | | | X
Westra, 2015^83^ | | | | X
Willekens, 2011^84^ | | | | | X

### References to Appendix D: KQ 1 Excluded Studies

1 Albahri OS, Albahri AS, Mohammed KI, . Systematic Review of Real-time Remote Health Monitoring System in Triage and Priority-Based Sensor Technology: Taxonomy, Open Challenges, Motivation and Recommendations. J Med Syst. 2018;42(5):1–1.
2 Andrews V. Using telemedicine in clinical decision-making. Practice Nursing. 2014;25(1):42–46.
3 Nurse telephone triage in out of hours primary care: a pilot study. South Wiltshire Out of Hours Project (SWOOP) Group. BMJ. 1997;314(7075):198–9.9022437
4 A new telehealth service. Kai Tiaki Nursing New Zealand. 2015;21(6):9–9.
5 Nurses’ use of decision-support software for telephone triage. Primary Health Care. 2015;25(3):15–15.
6 No one day is the same… says Amelia Mawhinney. Kai Tiaki Nursing New Zealand. 2015;21(2):47–47.
7 Same-day GP and nurse-led telephone triage v usual care. Primary Health Care. 2014;24(8):15–15.
8 Bearden MB, Brown T, Kirksey KM, . Easing the chaos in emergency departments: implementation of the ‘ask your nurse’ teletriage program. J Emerg Nurs. 2008;34(3):221–4.18558253
9 Bergmo TS, Kummervold PE, Gammon D, . Electronic patient-provider communication: will it offset office visits and telephone consultations in primary care? Int J Med Inform. 2005;74(9):705–10.16095961
10 Biermann E, Dietrich W, Rihl J, . Are there time and cost savings by using telemanagement for patients on intensified insulin therapy? A randomised, controlled trial. Comput Methods Programs Biomed. 2002;69(2):137–46.12100793
11 Blank L, Coster J, O’Cathain A, . The appropriateness of, and compliance with, telephone triage decisions: a systematic review and narrative synthesis. J Adv Nurs. 2012;68(12):2610–21.22676805
12 Campbell JL, Fletcher E, Britten N, . The clinical effectiveness and cost-effectiveness of telephone triage for managing same-day consultation requests in general practice: a cluster randomised controlled trial comparing general practitioner-led and nurse-led management systems with usual care (the ESTEEM trial). Health Technol Assess. 2015;19(13):1–212, vii–viii.
13 Carrasqueiro S, Oliveira M, Encarnacao P. Evaluation of telephone triage and advice services: a systematic review on methods, metrics and results. Stud Health Technol Inform. 2011;169:407–11.21893782
14 Castro LA, Favela J, Garcia-Pena C. Effects of communication media choice on the quality and efficacy of emergency calls assisted by a mobile nursing protocol tool. Comput Inform Nurs. 2014;32(11):550–8.25251859
15 Chmiel C, Huber CA, Rosemann T, . Walk-ins seeking treatment at an emergency department or general practitioner out-of-hours service: a cross-sectional comparison. BMC Health Serv Res. 2011;11:94.21554685
16 Cronin RM, Fabbri D, Denny JC, . A comparison of rule-based and machine learning approaches for classifying patient portal messages. Int J Med Inform. 2017;105:110–120.28750904
17 Dale J, Shrimpton L. Managing telephone assessment and triage. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2011(58):78–79.
18 de Coster C, Quan H, Elford R, . Follow-through after calling a nurse telephone advice line: A population-based study. Fam Pract. 2010;27(3):271–278.20215333
19 Downes MJ, Mervin MC, Byrnes JM, . Telephone consultations for general practice: a systematic review. Syst Rev. 2017;6(1):128.28673333
20 Dunt D, Day SE, Kelaher M, . The impact of standalone call centres and GP cooperatives on access to after hours GP care: a before and after study adjusted for secular trend. Fam Pract. 2006;23(4):453–60.16702188
21 Dunt D, Wilson R, Day SE, . Impact of telephone triage on emergency after hours GP Medicare usage: a time-series analysis. Aust New Zealand Health Policy. 2007;4:21.17927836
22 Eccles G, Edwards A. Evaluating a service improvement intervention in GP out-of-hours: impact of ‘expert triage model’. Qual Prim Care. 2015;23(1):9–17.
23 Eppes CS, Garcia PM, Grobman WA. Telephone triage of influenza-like illness during pandemic 2009 H1N1 in an obstetric population. Am J Obstet Gynecol. 2012;207(1):3–8.22464291
24 Garratt AM, Danielsen K, Hunskaar S. Patient satisfaction questionnaires for primary care out-of-hours services: a systematic review. Br J Gen Pract. 2007;57(542):741–7.17761062
25 Godfrey K. Nurse-led triage in general practice. Nurs Times. 2006;102(13):42–3.
26 Gulacti U. Comparison of secure messaging application (WhatsApp) and standard telephone usage for consultations on Length of Stay in the ED. Appl Clin Inform. 2017;8(3):742–753.28880047
27 Gulacti U, Lok U. Comparison of secure messaging application (WhatsApp) and standard telephone usage for consultations on Length of Stay in the ED. A prospective randomized controlled study. Appl Clin Inform. 2017;8(3):742–753.28880047
28 Hansen BL, Munck A. Out-of-hours service in Denmark: The effect of a structural change. British Journal of General Practice. 1998;48(433):1497–1499.10024709
29 Holroyd BR, Bullard MJ, Latoszek K, . Impact of a triage liaison physician on emergency department overcrowding and throughput: a randomized controlled trial. Acad Emerg Med. 2007;14(8):702–8.17656607
30 Howard M, Goertzen J, Hutchison B, . Patient satisfaction with care for urgent health problems: a survey of family practice patients. Ann Fam Med. 2007;5(5):419–24.17893383
31 Howell T. ED Utilization by Uninsured and Medicaid Patients after Availability of Telephone Triage. JEN: Journal of Emergency Nursing. 2016;42(2):120–124.26409919
32 Huber CA, Rosemann T, Zoller M, . Out-of-hours demand in primary care: Frequency, mode of contact and reasons for encounter in Switzerland. J Eval Clin Pract. 2011;17(1):174–179.20831666
33 Huibers L, Smits M, Renaud V, . Safety of telephone triage in out-of-hours care: a systematic review. Scand J Prim Health Care. 2011;29(4):198–209.22126218
34 Huibers L, Keizer E, Giesen P, . Nurse telephone triage: good quality associated with appropriate decisions. Fam Pract. 2012;29(5):547–52.22327415
35 Jackman J. Telephone services. Holding the line. Health Serv J. 1998;108(5608):28–9.
36 Jones G, Brennan V, Jacques R, . Evaluating the impact of a ‘virtual clinic’ on patient experience, personal and provider costs of care in urinary incontinence: A randomised controlled trial. PLoS ONE. 2018;13(1).
37 Katz SJ, Moyer CA, Cox DT, . Effect of a triage-based e-mail system on clinic resource use and patient and physician satisfaction in primary care: A randomized controlled trial. J Gen Intern Med. 2003;18(9):736–744.12950483
38 Kim SE, Michalopoulos C, Kwong RM, . Telephone care management’s effectiveness in coordinating care for medicaid beneficiaries in managed care: A randomized controlled study. Health Serv Res. 2013;48(5):1730–1749.23557249
39 Klasner AE, King WD, Crews TB, . Accuracy and response time when clerks are used for telephone triage. Clin Pediatr (Phila). 2006;45(3):267–9.16708141
40 Knight K, Endacott R, Kenny A. Ambiguous and arbitrary: The role of telephone interactions in rural health service delivery. Australian Journal of Primary Health. 2010;16(2):126–131.21128573
41 Krumperman K, Weiss S, Fullerton L. Two Types of Prehospital Systems Interventions that Triage Low-Acuity Patients to Alternative Sites of Care. South Med J. 2015;108(7):381–6.26192931
42 Liedberg F, Gerdtham U, Gralen K, . Fast-track access to urologic care for patients with macroscopic haematuria is efficient and cost-effective: results from a prospective intervention study. Br J Cancer. 2016;115(7):770–5.27560554
43 Lin CT, Wittevrongel L, Moore L, . An internet-based patient-provider communication system: Randomized controlled trial. J Med Internet Res. 2005;7(4).
44 Mallett R, Bakker E, Burton M. Is physiotherapy self-referral with telephone triage viable, cost-effective and beneficial to musculoskeletal outpatients in a primary care setting? Musculoskeletal Care. 2014;12(4):251–60.24863858
45 Manzo-Silberman S, Assez N, Vivien B, . Management of non-traumatic chest pain by the French Emergency Medical System: Insights from the DOLORES registry. Arch Cardiovasc Dis. 2015;108(3):181–8.25662700
46 Marsh E. EB51 Virtual Intensive Care Unit: Meeting the Need for Critical Care of Rural Veterans. Critical Care Nurse. 2014;34(2):e2–3.
47 Mayor S. Primary care telephone triage does not reduce workload, study finds. BMJ. 2014;349(7970):2–2.
48 Melnyk BM. The latest evidence on telehealth interventions to improve patient outcomes. Worldviews Evid Based Nurs. 2008;5(3):163–166.
49 Morrissey J. On call. Foundation Health Systems’ sophisticated telephone triage center gains popularity with patients and physicians. Mod Healthc. 1997;27(34):72, 74–6, 78–80.
50 Murdoch J, Varley A, Fletcher E, . Implementing telephone triage in general practice: a process evaluation of a cluster randomised controlled trial. BMC Fam Pract. 2015;16:47.25887747
51 Nagle JP, McMahon K, Barbour M, . Evaluation of the use and usefulness of telephone consultations in one general practice. British Journal of General Practice. 1992;42(358):190–193.1389429
52 Navratil-Strawn JL, Hawkins K, Wells TS, . Listening to the nurse pays off: an integrated Nurse Health Line programme was associated with significant cost savings. J Nurs Manag. 2014;22(7):837–847.23607510
53 O’Keeffe N. The effect of a new general practice out-of-hours co-operative on a county hospital accident and emergency department. Ir J Med Sci. 2008;177(4):367–370.18751757
54 O’Malley AS. After-hours access to primary care practices linked with lower emergency department use and less unmet medical need. Health Affairs. 2013;32(1):175–183.23242631
55 Ong RS, Post J, van Rooij H, . Call-duration and triage decisions in out of hours cooperatives with and without the use of an expert system. BMC Fam Pract. 2008;9:11.18271970
56 Philips H, Remmen R, Van Royen P, . What’s the effect of the implementation of general practitioner cooperatives on caseload? Prospective intervention study on primary and secondary care. BMC Health Serv Res. 2010;10:222.20673342
57 Philips H, Mahr D, Remmen R, . Predicting the place of out-of-hours care-A market simulation based on discrete choice analysis. Health Policy. 2012;106(3):284–290.22595229
58 Purc-Stephenson RJ, Thrasher C. Patient compliance with telephone triage recommendations: A meta-analytic review. Patient Educ Couns. 2012;87(2):135–142.22001679
59 Rahmqvist M, Ernesäter A, Holmström I. Triage and patient satisfaction among callers in Swedish computer-supported telephone advice nursing. J Telemed Telecare. 2011;17(7):397–402.21983224
60 Richards SH, Winder R, Seamark D, . Accessing out-of-hours care following implementation of the GMS contract: An observational study. British Journal of General Practice. 2008;58(550):331–338.18482487
61 Roberts J. The telephone consultation process: part II. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2007(36):76–80.
62 Roberts J. Telephone consultation and risk management. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2007(35):75–77.
63 Roth A, Rogowski O, Yanay Y, . Teleconsultation for cardiac patients: a comparison between nurses and physicians: the SHL experience in Israel. Telemed J E Health. 2006;12(5):528–34.17042705
64 Rouse DJ. [Commentary on] Early labor assessment and support at home versus telephone triage: a randomized controlled trial. Obstetrical & Gynecological Survey. 2007;62(5):287–288.
65 Salk ED, Schriger DL, Hubbell KA, . Effect of visual cues, vital signs, and protocols on triage: a prospective randomized crossover trial. Ann Emerg Med. 1998;32(6):655–64.9832660
66 Shannon GR, Wilber KH, Allen D. Reductions in costly healthcare service utilization: findings from the Care Advocate Program. J Am Geriatr Soc. 2006;54(7):1102–7.16866682
67 Shekelle P, Roland M. Nurse-led telephone-advice lines. Lancet. 1999;354(9173):88–9.10408478
68 Smits M, Huibers L, Oude Bos A, . Patient satisfaction with out-of-hours GP cooperatives: a longitudinal study. Scand J Prim Health Care. 2012;30(4):206–13.23113756
69 Smits M, Keizer E, Ram P, . Development and testing of the KERNset: an instrument to assess the quality of telephone triage in out-of-hours primary care services. BMC Health Serv Res. 2017;17(1):798.29197376
70 Smitsa M, Hanssena S, Huibersa L, . Telephone triage in general practices: A written case scenario study in the Netherlands. Scand J Prim Health Care. 2016;34(1):28–36.26893132
71 Somers M. Enhancing customer service in the admitting process. Healthc Financ Manage. 1994;48(9):68, 70.
72 Soulleihet V, Nicoli F, Trouve J, . Optimized acute stroke pathway using medical advanced regulation for stroke and repeated public awareness campaigns. Am J Emerg Med. 2014;32(3):225–32.24361139
73 Spaulding AB, Radi D, Macleod H, . Design and implementation of a statewide influenza nurse triage line in response to pandemic H1N1 influenza. Public Health Rep. 2012;127(5):532–40.22942472
74 Stacey D, Carley M, Kohli J, . Remote symptom support training programs for oncology nurses in Canada: an environmental scan. Can Oncol Nurs J. 2014;24(2):78–88.24902425
75 Stuart A, Rogers S, Modell M. Evaluation of a direct doctor-patient telephone advice line in general practice. British Journal of General Practice. 2000;50(453):305–306.10897515
76 Takala J, Vehviläinen A, Eräpohja A, . The list system can reduce the waiting time and number of consultations in a centralized primary care centre that provides out of hours medical care. Scand J Prim Health Care. 1997;15(1):48–51.9101625
77 Thompson F, George S, Lattimer V, . Overnight calls in primary care: randomised controlled trial of management using nurse telephone consultation. BMJ. 1999;319(7222):1408.10574857
78 Turner D. An exploratory study of physiotherapy telephone assessment…Including commentary by Foster NE. International Journal of Therapy & Rehabilitation. 2009;16(2):97–105.
79 Valsangkar NP, Eppstein AC, Lawson RA, . Effect of Lean Processes on Surgical Wait Times and Efficiency in a Tertiary Care Veterans Affairs Medical Center. JAMA Surg. 2017;152(1):42–47.27603225
80 van Ierland Y, van Veen M, Huibers L, . Validity of telephone and physical triage in emergency care: the Netherlands Triage System. Fam Pract. 2011;28(3):334–41.21106645
81 Van Uden CJT, Ament AJHA, Hobma SO, . Patient satisfaction with out-of-hours primary care in the Netherlands. BMC Health Serv Res. 2005;5.
82 Villarreal M, Leach J, Ngianga-Bakwin K, . Can a partnership between general practitioners and ambulance services reduce conveyance to emergency care? Emergency Medicine Journal. 2017;34(7):459–465.28420688
83 Westra I, Niessen FB. Implementing Real-Time Video Consultation in Plastic Surgery. Aesthetic Plast Surg. 2015;39(5):783–90.26169952
84 Willekens M, Giesen P, Plat E, . Quality of after-hours primary care in the Netherlands: Adherence to national guidelines. BMJ Quality and Safety. 2011;20(3):223–227.

## KQ 2 Excluded Studies

Exclusion reason Study | Not full publication | Not eligible country | Not population of interest | Not eligible setting | Not eligible intervention | Not eligible design | Not eligible outcome
Allan, 2014^1^ | | | | | | | X
Allen, 2008^2^ | X
Allen, 2008^3^ | | | | X
Anderson, 2015^4^ | | | | | | | X
Andreao, 2015^5^ | | X
Anonymous, 1997^6^ | | | | | | X
Anonymous, 1997^7^ | | | | | X
Anonymous, 1998^8^ | | | X
Anonymous, 2001^9^ | X
Anonymous, 2003^10^ | X
Anonymous, 2005^11^ | | | | | | | X
Anonymous, 2006^12^ | X
Anonymous, 2014^13^ | | | | | | X
Anonymous, 2015^14^ | X
Anonymous, 2015^15^ | | | | | | | X
Aranda, 2001^16^ | | | | X
Arioto, 2000^17^ | X
Arioto, 2000^18^ | X
Atherton, 2018^19^ | | | | | X
Atherton, 2018^20^ | | | | | X
Bagayoko, 2014^21^ | | X
Barrett, 2017^22^ | | | | | X
Baylis, 2012^23^ | | | | | | X
Bjorkman, 2018^24^ | | | X
Blanchfield, 1997^25^ | | | | | | X
Blinkenberg, 2013^26^ | X
Boidron, 2016^27^ | | | | | | | X
Bolton, 2002^28^ | | | | | | X
Boxer, 2008^29^ | X
Brant, 2018^30^ | | | | | X
Brennan, 1992^31^ | | | | | | X
Britnell, 2005^32^ | X
Brown, 2012^33^ | | | | | | | X
Brunett, 2015^34^ | | | | | | X
Buja, 2015^35^ | | | | | | | X
Bunn, 2005^36^ | | | | | | | X
Buppert, 2009^37^ | X
Busk Nørøxe, 2017^38^ | | | | | | | X
Busk Nørøxe, 2017^39^ | | | | | | X
Cady, 1999^40^ | X
Cady, 1999^41^ | X
Car, 2003^42^ | | | | | X
Car, 2004^43^ | | | | | | X
Caralis, 2010^44^ | | | | | | | X
Castellote, 2016^45^ | X
Chang, 2001^46^ | | | | | | X
Charles-Jones, 2003^47^ | | | | | | | X
Chow, 2008^48^ | | X
Christensen, 1998^49^ | | | | | | | X
Clawson, 2001^50^ | | | | X
Clay-Williams, 2017^51^ | | | | | X
Coleman, 1997^52^ | X
Comino, 2007^53^ | | | | | X
Connechen, 2006^54^ | | | | | | X
Cook, 2015^55^ | | | | | | | X
Coombes, 2016^56^ | X
Cosford, 2010^57^ | X
Cragg, 1994^58^ | | | | | | | X
Craig, 2015^59^ | | | | | | | X
Crouch, 1999^60^ | | | | | | | X
Cunningham, 2012^61^ | | | | | X
Custer, 2003^62^ | | | | | | X
Dahlgren, 2017^63^ | | | | | X
Dale, 1998^64^ | | | | | | X
Dale, 2011^65^ | | | | | | | X
de Almeida Barbosa, 2016^66^ | | | | | | X
Demiris, 2004^67^ | | | | | X
Derkx, 2009^68^ | | | | | | X
Derkx, 2008^69^ | | | | | | X
DeVore, 1999^70^ | | | | | | X
Doughty, 2008^71^ | | | | | | X
Downes, 2017^72^ | | | | | X
Drennan, 2015^73^ | X
Dundas, 1998^74^ | X
Dunt, 2006^75^ | | | | | | X
Dunt, 2005^76^ | | | | | | X
Eastwood, 2018^77^ | | | | | | | X
Eastwood, 2017^78^ | | | | | | | X
Edmonds, 1997^79^ | | | | | | | X
Edwards, 2017^80^ | | | | | | X
Ek, 2015^81^ | | | X
Elnicki, 2000^82^ | | | | | X
Eminovic, 2004^83^ | | | | | | X
Erdman, 2001^84^ | | | | | X
Ernesäter, 2010^85^ | | | | | | X
Fletcher, 1999^86^ | | | | | X
Flynn, 1998^87^ | | | | | | | X
Foels, 2004^88^ | | | | | | X
Fortune, 2001^89^ | | | | | | | X
Gaffney, 2001^90^ | | | X
Gallagher, 1998^91^ | X
Gardner, 2010^92^ | | | | | | X
George, 1995^93^ | | | | | | X
George, 1995^94^ | | | | | | X
Gerard, 2006^95^ | | | | | | | X
Giesen, 2007^96^ | | | | | | | X
Giesen, 2007^97^ | | | | | | X
Gill, 1999^98^ | X
Gillen, 2010^99^ | | | | | | X
Gobis, 1997^100^ | X
Godden, 2011^101^ | | | | | | X
Godfrey, 2006^102^ | | | | | | | X
Gonzalez, 2015^103^ | | | | | X
Goode, 2004^104^ | | | | | X
Goransson, 2003^105^ | | | | | X
Göransson, 2005^106^ | | | | | | X
Graber, 2003^107^ | X
Grady, 2007^108^ | | | | | X
Grenier, 2000^109^ | | | | | | X
Griffin, 2017^110^ | | | | | | X
Gustafsson, 2016^111^ | X
Hagan, 2000^112^ | X
Healy, 2000^113^ | | | | | X
Heath, 2007^114^ | | | | | | X
Hildebrandt, 2006^115^ | | | | | | X
Hildebrandt, 2003^116^ | | | | | | | X
Hoare, 1999^117^ | | | | | | | X
Hogenbirk, 2005^118^ | | | | | X
Holmstrom, 2002^119^ | | | | | | X
Holt, 2016^120^ | X
Huibers, 2012^121^ | | | | | X
Jackman, 1998^122^ | | | | | | | X
Jang-Jaccard, 2014^123^ | | | | | | | X
Jayaraman, 2008^124^ | | | | | X
Jiwa, 2002^125^ | | | | | | X
Johansson, 2014^126^ | | | | | | X
Johnson, 2015^127^ | | | | | | X
Johnson, 2015^128^ | | | | | X
Johnson, 1995^129^ | | | | | X
Jones, 2017^130^ | | | | | | | X
Jones, 2003^131^ | | | | | | | X
Jones, 1998^132^ | | | | | | X
Jones, 2012^133^ | | | | | X
Jung, 2015^134^ | | | | | | | X
Kaakinen, 2016^135^ | | | X
Kaakinen, 2016^136^ | | | | | | X
Kaminsky, 2017^137^ | | | | | | X
Katz, 2003^138^ | X
Khan, 2013^139^ | X
Kiddy, 2005^140^ | | | | | X
Kishner, 1997^141^ | | | | | | X
Knight, 2015^142^ | | | | | X
Knowles, 2014^143^ | | | | | | X
Koivunen, 2018^144^ | | | | | | X
Kwon, 2007^145^ | | | | | | X
Labarere, 2003^146^ | | | | | | X
Lake, 2016^147^ | X
Langabeer, 2017^148^ | | | | | X
Larson-Dahn, 2001^149^ | | | | | | X
Lattimer, 2005^150^ | | | | | X
Lattimer, 2000^151^ | | | | | X
Leclerc, 2003^152^ | | | | | X
Leibowitz, 2003^153^ | | | | | | X
Leng, 2016^154^ | | | | | | X
Leshem-Rubinow, 2015^155^ | | | | | X
Leutgeb, 2014^156^ | | | | | | | X
Liederman, 2005^157^ | | | | | | X
Lin, 2005^158^ | | | | | X
Ling, 2016^159^ | | | | | | X
Loane, 2002^160^ | | | | | X
Locatis, 2010^161^ | X
Lowes, 1997^162^ | | | | | X
Madlon-Kay, 1991^163^ | | | | | | X
Manuel, 1993^164^ | | | | | | X
Marklund, 2007^165^ | | | | | | X
Marklund, 1991^166^ | | | | | X
Marklund, 1990^167^ | | | X
Martin, 1995^168^ | X
Martinsson, 2018^169^ | X
Marvicsin, 2015^170^ | X
Maynard, 2004^171^ | | | | | X
Mayor, 2014^172^ | | X
McCarthy, 1995^173^ | | | | | | | X
McKenzie, 2016^174^ | X
McKenzie, 2016^175^ | X
McKenzie, 2016^176^ | X
McKenzie, 2016^177^ | | | | | X
McKinstry, 2002^178^ | | | | | | | X
McNeil, 2007^179^ | | | | | X
McNicholas, 2018^180^ | | | | | | X
Meng, 2015^181^ | | | | | | X
Midtbo, 2017^182^ | | | | | | | X
Moffatt, 2011^183^ | X
Mohammed, 2012^184^ | | | | | | X
Moll van Charante, 2006^185^ | | | | | | | X
Moll van Charante, 2006^186^ | | | | | X
Monsuez, 2009^187^ | X
Montalto, 2010^188^ | | | | | | | X
Moore, 2002^189^ | | | | | | | X
Moriarty, 2003^190^ | | | | | X
Morimura, 2005^191^ | | | | | | X
Morrow, 2005^192^ | X
Moth, 2014^193^ | | | X
Moth, 2013^194^ | X
Mounce, 2016^195^ | | | | | | | X
Munro, 2003^196^ | | | | | | X
Murphy, 2000^197^ | | | | | | | X
Narasimha, 2017^198^ | | | | | X
Nemes, 2011^199^ | X
Newbould, 2017^200^ | X
Newton, 2006^201^ | X
Niemann, 2004^202^ | X
Niv, 2018^203^ | X
North, 2014^204^ | | | | | X
O’Cathain, 2014^205^ | | | | | X
O’Cathain, 2003^206^ | | | | | X
Olesen, 1994^207^ | | | | | | X
O’Malley, 2012^208^ | | | | | | | X
Ong, 2008^209^ | | | | | X
Onubogu, 2013^210^ | | | | | | | X
Owens, 2017^211^ | | | | | | | X
Palma, 2014^212^ | | | | | | X
Pancer, 2018^213^ | X
Philips, 2015^214^ | | | | | | | X
Poole, 2011^215^ | | | | | | X
Pooley, 2003^216^ | | | | | X
Pope, 2017^217^ | | | | | X
Posocco, 2018^218^ | | | | | | X
Proctor, 2002^219^ | | | | | | X
Quallich, 2003^220^ | | | | | | X
Reisinger, 1998^221^ | | | X
Richards, 2000^222^ | | | | | | | X
Ritter, 2010^223^ | | | | | | | X
Roberts, 1998^224^ | X
Roberts, 2007^225^ | | | | | | X
Roberts, 2007^226^ | | | | | | X
Robinson, 1996^227^ | | | | | | X
Rodway, 2013^228^ | | | | | | X
Roing, 2015^229^ | | | | | X
Rortveit, 2013^230^ | | | | | | X
Rosenblatt, 2001^231^ | | | | | | | X
Rutenberg, 2000^232^ | | | | | | | X
Rutenberg, 2000^233^ | | X
Rutenberg, 2008^234^ | | | | | X
Sagrillo, 2002^235^ | | | | | X
Sakurai, 2014^236^ | | | | | | | X
Salisbury, 2005^237^ | X
Salisbury, 2000^238^ | | | | | | X
Salisbury, 1997^239^ | | | | | | X
Salk, 1998^240^ | | | | | X
Salman, 2014^241^ | | X
Sanderson, 2008^242^ | | | X
Sands, 2013^243^ | | | | | | X
Sandvik, 2018^244^ | | | | | | X
Sapien, 2000^245^ | | | | X
Schlachta-Fairchild, 2010^246^ | | | | | | X
Schoenfeld, 2016^247^ | | | | | X
Scott-Jones, 2008^248^ | | | | | | X
Shani, 2015^249^ | | | | | | X
Shekelle, 1999^250^ | | | | | | | X
Simonsen-Anderson, 2002^251^ | | | | | | X
Simpson, 2000^252^ | | | | | X
Singh, 2013^253^ | X
Skorin-Kapov, 2010^254^ | | | | | | X
Smith, 2001^255^ | | | | X
Smits, 2017^256^ | | | X
Smits, 2017^257^ | | | | | X
Smits, 2016^258^ | | | | | X
Smitsa, 2016^259^ | | | | | | X
Snooks, 2009^260^ | X
Spence, 2012^261^ | X
Sprivulis, 2004^262^ | | | | | X
Srámek, 1994^263^ | | | | | | | X
Stern, 2017^264^ | X
Storhaug, 2017^265^ | | | | | | X
Stowe, 2010^266^ | | | | | | X
Ström, 2011^267^ | | | | | X
Swage, 2013^268^ | | | | | X
Thompson, 1999^269^ | X
Tran, 2017^270^ | | | | | | | X
Tranberg, 2018^271^ | | | | | | X
Tuckson, 2017^272^ | | | | | | X
Tuden, 2017^273^ | | | | | X
Turner, 2002^274^ | | | | | X
van der Biezen, 2017^275^ | | | | | | | X
Van Der Biezen, 2016^276^ | X
van Galen, 2018^277^ | | | | | | X
van Ierland, 2011^278^ | X
van Uden, 2006^279^ | | | | | X
Verzantvoort, 2018^280^ | X
Vitacca, 2009^281^ | | | | | X
Wallace, 2002^282^ | | | | X
Warren, 2015^283^ | | | | | | | X
Wheeler, 2015^284^ | | | | | | X
Wheeler, 2000^285^ | X
Willson, 2003^286^ | X
Wootton, 2001^287^ | | | | | X
Wouters, 2016^288^ | X
Youssef, 2000^289^ | | | | | X
Zummo, 2015^290^ | | | | X

### References to Appendix D: KQ 2 Excluded Studies

1 Allan JL, Farquharson B, Johnston DW, . Stress in telephone helpline nurses is associated with failures of concentration, attention and memory, and with more conservative referral decisions. Br J Psychol. 2014;105(2):200–13.24754808
2 Allen D, Chasse MA, Hogg D, . Review of policy and practice consultations 2006-2007. Alta RN. 2008;64(3):7–10.18444301
3 Allen D, Chassé MA, Hogg D, . Review of policy and practice consultations 2006-2007. Alberta RN / Alberta Association of Registered Nurses. 2008;64(3):7–10.
4 Anderson A, Roland M. Potential for advice from doctors to reduce the number of patients referred to emergency departments by NHS 111 call handlers: observational study. BMJ Open. 2015;5(11):e009444.
5 Andreao RV, Schimidt MQ, Sarti TD, . Implementation of a Teleconsultation Service in the Primary Health Care in Brazil. Stud Health Technol Inform. 2015;216:888.26262190
6 Anonymous. Nurse telephone triage in out of hours primary care: a pilot study. South Wiltshire Out of Hours Project (SWOOP) Group. BMJ. 1997;314(7075):198–9.9022437
7 Anonymous. Charting tips. Documenting telephone advice. Nursing. 1997;27(9):71–71.
8 Anonymous. Nurses can safely manage half of out of hours calls in primary care. BMJ. 1998;317(7165):G.
9 Anonymous. ED makes nurses happy by outsourcing calls. ED Manag. 2001;13(10):113–5.11577508
10 Anonymous. EMTALA on-call coverage rule. Hosp Law Newsl. 2003;21(2):1–6.
11 Anonymous. Beware the dangers of telephone triage. Occupational Health. 2005;57(6):11–11.
12 Anonymous. ‘Telephone triage’ is ‘risky business’ for nurses. Nurs Law Regan Rep. 2006;46(10):2.
13 Anonymous. Same-day GP and nurse-led telephone triage v usual care. Primary Health Care. 2014;24(8):15–15.
14 Anonymous. Out-of-hours provider launches telephone triage centre. Vet Rec. 2015;177(3):58.
15 Anonymous. Nurses’ use of decision-support software for telephone triage. Primary Health Care. 2015;25(3):15–15.
16 Aranda S, Hayman-White K, Devilee L, . Inpatient hospice triage of ‘after-hours’ calls to a community palliative care service. Int J Palliat Nurs. 2001;7(5):214–20.12148971
17 Arioto C. Telephone triage: protocols and clinical judgment are not mutually exclusive. J Emerg Nurs. 2000;26(3):203.10839835
18 Arioto C, Rutenberg CD. Telephone triage: protocols and clinical judgment are not mutually exclusive…in response to an article by Carol Dare Rutenberg in the February issue of the Journal (What do we really KNOW about telephone triage? 2000;26:76-8). JEN: Journal of Emergency Nursing. 2000;26(3):203–204.10839835
19 Atherton H, Brant H, Ziebland S, . Health Services and Delivery Research. The potential of alternatives to face-to-face consultation in general practice, and the impact on different patient groups: a mixed-methods case study. Southampton (UK): NIHR. Journals LibraryCopyright (c) Queen’s Printer and Controller of HMSO 2018.
20 Atherton H, Brant H, Ziebland S, . Alternatives to the face-to-face consultation in general practice: focused ethnographic case study. Br J Gen Pract. 2018;68(669):e293–e300.29378697
21 Bagayoko CO, Traore D, Thevoz L, . Medical and economic benefits of telehealth in low- and middle-income countries: results of a study in four district hospitals in Mali. BMC Health Serv Res. 2014;14: Suppl 1:S9.25080312
22 Barrett D. Rethinking presence: a grounded theory of nurses and teleconsultation. J Clin Nurs. 2017;26(19/20):3088–3098.27874982
23 Baylis D. Minimising the risks in telephone triage. Practice Nurse. 2012;42(15):24–25.
24 Bjorkman A, Salzmann-Erikson M. When all other doors are closed: Telenurses’ experiences of encountering care seekers with mental illnesses. Int J Ment Health Nurs. 2018.
25 Blanchfield KC, Schwarzentraub L, Reisinger PB. Development of telephone nursing practice standards. Nurs Econ. 1997;15(5):265–7.9362870
26 Blinkenberg J, Morken T. House officers-a part of emergency primary health care. Tidsskr Nor Laegeforen. 2013;133(4):385–6.23423201
27 Boidron L, Boudenia K, Avena C, . Emergency medical triage decisions are swayed by computer-manipulated cues of physical dominance in caller’s voice. Sci Rep. 2016;6:30219.27456205
28 Bolton P, Gannon S, Aro D. HealthConnect: a trial of an after-hours telephone triage service. Aust Health Rev. 2002;25(2):95–103.
29 Boxer RJ, Carabello L, Doarn CR, . Telephone-based medical consultations. Telemed J E Health. 2008;14(4):323–9.18570560
30 Brant HD, Atherton H, Bikker A, . Receptionists’ role in new approaches to consultations in primary care: a focused ethnographic study. Br J Gen Pract. 2018;68(672):e478–e486.29866710
31 Brennan M. Nursing process in telephone advice. Nurs Manage. 1992;23(5):62–4, 66.
32 Britnell M. On the on-call conundrum. Health Serv J. 2005;115(5965):17.
33 Brown S, Henderson E, Howse J, . Patient views of single number access to urgent care services. Fam Pract. 2012;29(6):713–8.22417779
34 Brunett PH, DiPiero A, Flores C, . Use of a voice and video internet technology as an alternative to in-person urgent care clinic visits. J Telemed Telecare. 2015;21(4):219–26.25697491
35 Buja A, Toffanin R, Rigon S, . Out-of-hours primary care services: demands and patient referral patterns in a Veneto region (Italy) Local Health Authority. Health Policy. 2015;119(4):437–46.25620776
36 Bunn F, Byrne G, Kendall S. The effects of telephone consultation and triage on healthcare use and patient satisfaction: a systematic review. Br J Gen Pract. 2005;55(521):956–61.16378566
37 Buppert C. Guidelines for telephone triage. Dermatol Nurs. 2009;21(1):40–1.19283962
38 Busk Nørøxe K, Huibers L, Moth G, . Medical appropriateness of adult calls to Danish out-of-hours primary care: a questionnaire-based survey. BMC Fam Pract. 2017;18:1–9.28073347
39 Nørøxe KB, Huibers L, Moth G, . Medical appropriateness of adult calls to Danish out-of-hours primary care: a questionnaire-based survey. BMC Fam Pract. 2017;18(1):34.28292257
40 Cady R. Pitfalls in telephone triage. MCN Am J Matern Child Nurs. 1999;24(3):157.10326320
41 Cady R. Focus on the law. Telephone triage - avoiding the pitfalls. MCN: The American Journal of Maternal Child Nursing. 1999;24(4):209–209.
42 Car J, Sheikh A. Telephone consultations. BMJ. 2003;326(7396):966–9.12727771
43 Car J, Sheikh A. Email consultations in health care: 1 - Scope and effectiveness. British Medical Journal. 2004;329(7463):435–438.15321902
44 Caralis P. Teaching residents to communicate: the use of a telephone triage system in an academic ambulatory clinic. Patient Educ Couns. 2010;80(3):351–3.20688456
45 Castellote Varona FJ. Telephone consultations in a geriatrics clinic. Revista Espanola de Geriatria y Gerontologia. 2016;51(4):242–243.26564101
46 Chang BL, Mayo A, Omery A. Consumer satisfaction with telehealth advice-nursing. Stud Health Technol Inform. 2001;84(Pt 2):1435–9.11604963
47 Charles-Jones H, May C, Latimer J, . Telephone triage by nurses in primary care: what is it for and what are the consequences likely to be? J Health Serv Res Policy. 2003;8(3):154–9.12869341
48 Chow KM, Law MC, Szeto CC, . Telephone triage in peritoneal dialysis population. Hong Kong Journal of Nephrology. 2008;10(2):64–68.
49 Christensen MB, Olesen F. Out of hours service in Denmark: evaluation five years after reform. BMJ. 1998;316(7143):1502–5.9582141
50 Clawson JJ, Sinclair R. The emotional content and cooperation score in emergency medical dispatching. Prehospital Emergency Care. 2001;5(1):29–35.11194066
51 Clay-Williams R, Baysari M, Taylor N, . Service provider perceptions of transitioning from audio to video capability in a telehealth system: a qualitative evaluation. BMC Health Serv Res. 2017;17(1):558.28806903
52 Coleman A. Where do I stand? Legal implications of telephone triage. J Clin Nurs. 1997;6(3):227–31.9188340
53 Comino EJ, Zwar NA, Hermiz O. The Macarthur GP After-hours Service: a model of after-hours care for Australia. Aust Health Rev. 2007;31(2):223–30.17470043
54 Connechen J, Walter R. Telephone triage in general practice. Primary Health Care. 2006;16(2):36–40.
55 Cook EJ, Randhawa G, Guppy A, . A study of urgent and emergency referrals from NHS Direct within England. BMJ Open. 2015;5(5):e007533.
56 Coombes R. How to fix out of hours care. BMJ. 2016;353:i2356.27122149
57 Cosford PA, Thomas JM. Safer out of hours primary care. BMJ. 2010;340:c3194.20570866
58 Cragg DK, Campbell SM, Roland MO. Out of hours primary care centres: characteristics of those attending and declining to attend. BMJ. 1994;309(6969):1627–9.7819946
59 Craig J, Morris L, Cameron J, . An evaluation of the impact of the key information summary on GPs and out-of-hours clinicians in NHS Scotland. Scott Med J. 2015;60(3):126–31.25805773
60 Crouch R, Dale J, Visavadia B, . Provision of telephone advice from accident and emergency departments: a national survey. J Accid Emerg Med. 1999;16(2):112–3.10191444
61 Cunningham NJ, Weiland TJ, van Dijk J, . Telephone referrals by junior doctors: a randomised controlled trial assessing the impact of SBAR in a simulated setting. Postgrad Med J. 2012;88(1045):619–26.22893691
62 Custer M, O’Rourke KM, Roddy M, . The impact of a nursing triage line on the use of emergency department services in a military hospital. Mil Med. 2003;168(12):981–5.14719621
63 Dahlgren K, Holzmann MJ, Carlsson AC, . The use of a Swedish telephone medical advice service by the elderly - a population-based study. Scand J Prim Health Care. 2017;35(1):98–104.28277048
64 Dale J, Crouch R, Lloyd D. Primary care: nurse-led telephone triage and advice out-of-hours. Nurs Stand. 1998;12(47):41–5.
65 Dale J, Shrimpton L. Managing telephone assessment and triage. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2011(58):78–79.
66 de Almeida Barbosa I, da Conceição Dias da Silva KC, Araújo da Silva V, . The communication process in Telenursing: integrative review. Rev Bras Enferm. 2016;69(4):718–725.27508478
67 Demiris G, Edison K, Schopp LH. Shaping the future: needs and expectations of telehealth professionals. Telemed J E Health. 2004;10: Suppl 2:S-60–3.
68 Derkx H, Rethans JJ, Maiburg B, . New methodology for using incognito standardised patients for telephone consultation in primary care. Med Educ. 2009;43(1):82–8.19141001
69 Derkx HP, Rethans JJ, Muijtjens AM, . Quality of clinical aspects of call handling at Dutch out of hours centres: cross sectional national study. BMJ. 2008;337:a1264.18790814
70 DeVore NE. Telephone triage. A challenge for practicing midwives. J Nurse Midwifery. 1999;44(5):471–9.10540521
71 Doughty K, Monk A, Bayliss C, . Telecare, telehealth and assistive technologies: do we know what we’re talking about?…this article was originally published as Doughty K et al (2008) Telecare, telehealth and assistive technologies - do we know what we’re talking about? Journal of Assistive Technologies 1 (2) 6-10. Housing, Care & Support. 2008;11(3):36–41.
72 Downes MJ, Mervin MC, Byrnes JM, . Telephone consultations for general practice: a systematic review. Syst Rev. 2017;6(1):128.28673333
73 Drennan V. Evaluating the effects of telephone triage in general practice. Primary Health Care. 2015;25(5):15–15.
74 Dundas J, Casler C. Can I talk to a nurse? Nurs Manage. 1998;29(12):37–40.
75 Dunt D, Day SE, Kelaher M, . The impact of standalone call centres and GP cooperatives on access to after hours GP care: a before and after study adjusted for secular trend. Fam Pract. 2006;23(4):453–60.16702188
76 Dunt D, Day SE, Kelaher M, . Impact of standalone and embedded telephone triage systems on after hours primary medical care service utilisation and mix in Australia. Aust New Zealand Health Policy. 2005;2:30.16343354
77 Eastwood K, Morgans A, Stoelwinder J, . Patient and case characteristics associated with ‘no paramedic treatment’ for low-acuity cases referred for emergency ambulance dispatch following a secondary telephone triage: a retrospective cohort study. Scand J Trauma Resusc Emerg Med. 2018;26(1):8.29321074
78 Eastwood K, Smith K, Morgans A, . Appropriateness of cases presenting in the emergency department following ambulance service secondary telephone triage: a retrospective cohort study. BMJ Open. 2017;7(10):e016845.
79 Edmonds E. Telephone triage: 5 years’ experience. Accid Emerg Nurs. 1997;5(1):8–13.9069727
80 Edwards HB, Marques E, Hollingworth W, . Use of a primary care online consultation system, by whom, when and why: evaluation of a pilot observational study in 36 general practices in South West England. BMJ Open. 2017;7(11):e016901.
81 Ek B, Svedlund M. Registered nurses’ experiences of their decision-making at an Emergency Medical Dispatch Centre. J Clin Nurs. 2015;24(7-8):1122–31.25273221
82 Elnicki DM, Ogden P, Flannery M, . Telephone medicine for internists. J Gen Intern Med. 2000;15(5):337–43.10840269
83 Eminovic N, Wyatt JC, Tarpey AM, . First evaluation of the NHS direct online clinical enquiry service: a nurse-led web chat triage service for the public. J Med Internet Res. 2004;6(2):e17.15249266
84 Erdman C. The medicolegal dangers of telephone triage in mental health care. J Leg Med. 2001;22(4):553–79.11797504
85 Ernesäter A, Engström M, Holmström I, . Incident reporting in nurse-led national telephone triage in Sweden: The reported errors reveal a pattern that needs to be broken. J Telemed Telecare. 2010;16(5):243–247.20457800
86 Fletcher R. Telehealth rescues isolated patients. Health Manag Technol. 1999;20(11):52–3.
87 Flynn DM. Telephone triage as a strategy to ensure 24-hour access to medical care after the closure of supporting medical activity. Mil Med. 1998;163(10):702–6.9795548
88 Foels TJ, Terranova MD, Melzer SM. After-Hours Telephone Triage: Reducing the Financial Burden. Archives of Pediatrics and Adolescent Medicine. 2004;158(2):186.14757612
89 Fortune T. Telephone triage: an Irish view. Accid Emerg Nurs. 2001;9(3):152–6.11761869
90 Gaffney P, Crane S, Johnson G, . An analysis of calls referred to the emergency 999 service by NHS Direct. Emerg Med J. 2001;18(4):302–4.11435374
91 Gallagher M, Huddart T, Henderson B. Telephone triage of acute illness by a practice nurse in general practice: outcomes of care. Br J Gen Pract. 1998;48(429):1141–5.9667088
92 Gardner E. 24/7 primary care. Health Data Manag. 2010;18(3):96–7.20329479
93 George JE, Quattrone MS, Goldstone M. Emergency department telephone advice. J Emerg Nurs. 1995;21(5):450–1.7500580
94 George JE, Quattrone MS, Goldstone M. Phone consultations with the ED physician: is there nursing liability? J Emerg Nurs. 1995;21(2):163–4.7776611
95 Gerard K, Lattimer V, Surridge H, . The introduction of integrated out-of-hours arrangements in England: A discrete choice experiment of public preferences for alternative models of care. Health Expectations. 2006;9(1):60–69.16436162
96 Giesen P, Willekens M, Mokkink H, . Out-of-hours primary care: development of indicators for prescribing and referring. Int J Qual Health Care. 2007;19(5):289–95.17602203
97 Giesen P, Moll van Charante E, Mokkink H, . Patients evaluate accessibility and nurse telephone consultations in out-of-hours GP care: determinants of a negative evaluation. Patient Educ Couns. 2007;65(1):131–6.16939708
98 Gill PJ. IT system handles 3500 calls per day, with 20 second answer time. Kaiser Permanente takes the fast track to improving quality and increasing satisfaction. Health Manag Technol. 1999;20(1):20–1.
99 Gillen S. Telephone triage system launched to reduce ambulance call-outs. Emerg Nurse. 2010;18(3):7.
100 Gobis LJ. Reducing the risks of phone triage. Rn. 1997;60(4):61–3.9110875
101 Godden S, Hilton S, Pollock AM. Monitoring access to out-of-hours care services in Scotland - a review. J R Soc Med. 2011;104(4):162–72.21502215
102 Godfrey K. Nurse-led triage in general practice. Nurs Times. 2006;102(13):42–3.
103 Gonzalez M, Alqusairi D, Jackson A, . DIRECTING APPROPRIATE CARE. JEMS: Journal of Emergency Medical Services. 2015;40(11):53–66.
104 Goode J, Greatbatch D, O’Cathain A, . Risk and the responsible health consumer: the problematics of entitlement among callers to NHS Direct. Critical Social Policy. 2004;24(2):210–232.
105 Goransson K, Ehrenberg A, Ehnfors M. A national survey of emergency department triage in Sweden. AMIA Annu Symp Proc. 2003:851.14728356
106 Göransson KE, Ehrenberg A, Ehnfors M. Triage in emergency departments: National survey. J Clin Nurs. 2005;14(9):1067–1074.16164524
107 Graber DJ, Ardagh MW, O’Donovan P, . A telephone advice line does not decrease the number of presentations to Christchurch Emergency Department, but does decrease the number of phone callers seeking advice. N Z Med J. 2003;116(1177):U495.12861309
108 Grady JL, Schlachta-Fairchild L. Report of the 2004-2005 International Telenursing Survey. Comput Inform Nurs. 2007;25(5):266–72.17827989
109 Grenier S. Telephone triage and risk management. QRC Advis. 2000;16(5):9–12.
110 Griffin E, McCarthy JP, Thomas F, . New Zealand Healthline call data used to measure the effect of travel time on the use of the emergency department. Soc Sci Med. 2017;179:91–96.28260639
111 Gustafsson S. Influence of self-care advice on patient satisfaction and healthcare utilization. J Adv Nurs. 2016;72(8):1789–1799.27001441
112 Hagan L, Morin D, Lépine R. Evaluation of telenursing outcomes: satisfaction, self-care practices, and cost savings. Public health nursing (Boston, Mass.). 2000;17(4):305–313.
113 Healy P. Telephone triage can be dangerous, study warns. Nursing Standard. 2000;14(24):4–4.
114 Heath I. Out of hours primary care-a shambles? BMJ. 2007;334(7589):341.17303877
115 Hildebrandt DE, Westfall JM, Fernald DH, . Harm resulting from inappropriate telephone triage in primary care. J Am Board Fam Med. 2006;19(5):437–42.16951292
116 Hildebrandt DE, Westfall JM, Smith PC. After-hours telephone triage affects patient safety. J Fam Pract. 2003;52(3):222–7.12620177
117 Hoare K, Lacoste J, Haro K, . Exploring indicators of telephone nursing quality. J Nurs Care Qual. 1999;14(1):38–46.10575829
118 Hogenbirk JC, Pong RW, Lemieux SK. Impact of telephone triage on medical service use: implications for rural and remote areas. J Agric Saf Health. 2005;11(2):229–37.15931949
119 Holmstrom I, Dall’Alba G. ‘Carer and gatekeeper’ - conflicting demands in nurses’ experiences of telephone advisory services. Scand J Caring Sci. 2002;16(2):142–8.12000667
120 Holt TA, Fletcher E, Warren F, . Telephone triage systems in UK general practice: analysis of consultation duration during the index day in a pragmatic randomised controlled trial. Br J Gen Pract. 2016;66(644):e214–8.26917660
121 Huibers L, Giesen P, Smits M, . Nurse telephone triage in Dutch out-of-hours primary care: the relation between history taking and urgency estimation. Eur J Emerg Med. 2012;19(5):309–15.22008589
122 Jackman J. Telephone services. Holding the line. Health Serv J. 1998;108(5608):28–9.
123 Jang-Jaccard J, Nepal S, Alem L, . Barriers for delivering telehealth in rural australia: a review based on Australian trials and studies. Telemed J E Health. 2014;20(5):496–504.24801522
124 Jayaraman C, Kennedy P, Dutu G, . Use of mobile phone cameras for after-hours triage in primary care. J Telemed Telecare. 2008;14(5):271–4.18633004
125 Jiwa M, Mathers N, Campbell M. The effect of GP telephone triage on numbers seeking same-day appointments. Br J Gen Pract. 2002;52(478):390–1.12014537
126 Johansson AM, Söderberg S, Lindberg I. Views of residents of rural areas on accessibility to specialist care through videoconference. Technology and health care : official journal of the European Society for Engineering and Medicine. 2014;22(1):147–155.24561880
127 Johnson C, Wilhelmsson S, Borjeson S, . Improvement of communication and interpersonal competence in telenursing-development of a self-assessment tool. J Clin Nurs. 2015;24(11-12):1489–501.25393698
128 Johnson C, Wilhelmsson S, Börjeson S, . Improvement of communication and interpersonal competence in telenursing-development of a self-assessment tool. J Clin Nurs. 2015;24(11-12):1489–1501.25393698
129 Johnson BE, Schmitt BD, Wasson JH. Taming the telephone. Patient Care. 1995;29(11):136–156.
130 Jones RW, Despotou G, Arvanitis TN. Telehealth and the Re-Design of Emergency Medical Services. Stud Health Technol Inform. 2017;238:60–63.28679887
131 Jones D, Gill P, Harrison R, . An exploratory study of language interpretation services provided by videoconferencing. J Telemed Telecare. 2003;9(1):51–6.12641894
132 Jones K, Gilbert P, Little J, . Nurse triage for house call requests in a Tyneside general practice: patients’ views and effect on doctor workload. Br J Gen Pract. 1998;48(431):1303–6.9747546
133 Jones M, Hendricks JM, Cope V. Toward an Understanding of Caring in the Context of Telenursing. International Journal for Human Caring. 2012;16(1):7–15.
134 Jung EY, Kang HW, Park IH, . Proposal on the Establishment of Telemedicine Guidelines for Korea. Healthc Inform Res. 2015;21(4):255–64.26618032
135 Kaakinen P, Kyngas H, Tarkiainen K, . The effects of intervention on quality of telephone triage at an emergency unit in Finland: Nurses’ perspective. Int Emerg Nurs. 2016;26:26–31.26433605
136 Kaakinen P, Kyngäs H, Tarkiainen K, . The effects of intervention on quality of telephone triage at an emergency unit in Finland: Nurses’ perspective. Int Emerg Nurs. 2016;26:26–31.26433605
137 Kaminsky E, Röing M, Björkman A, . Telephone nursing in Sweden: A narrative literature review. Nurs Health Sci. 2017;19(3):278–286.28618087
138 Katz SJ, Moyer CA, Cox DT, . Effect of a triage-based e-mail system on clinic resource use and patient and physician satisfaction in primary care: A randomized controlled trial. J Gen Intern Med. 2003;18(9):736–744.12950483
139 Khan MN. Telephone consultations in primary care, how to improve their safety, effectiveness and quality. BMJ Qual Improv Rep. 2013;2(1).
140 Kiddy M, Lawrence S, Wild P, . Creating a new vision for primary care. Prof Nurse. 2005;20(6):18–21.
141 Kishner MJ, Robinson D, Anderson M, . Telephone triage. Nurse Practitioner. 1997;22(10):12–12.
142 Knight K, Kenny A, Endacott R. Assessing clinical urgency via telephone in rural Australia. Nurs Health Sci. 2015;17(2):201–7.25472637
143 Knowles E, O’Cathain A, Turner J, . Awareness and use of a new urgent care telephone service, NHS 111: cross-sectional population survey. J Health Serv Res Policy. 2014;19(4):224–30.24819379
144 Koivunen M, Saranto K. Nursing professionals’ experiences of the facilitators and barriers to the use of telehealth applications: a systematic review of qualitative studies. Scand J Caring Sci. 2018;32(1):24–44.28771752
145 Kwon WY, Rhee JE, Gang HS, . Triage method for out-of-hospital poisoned patients. J Korean Med Sci. 2007;22(2):336–41.17449946
146 Labarere J, Torres JP, Francois P, . Patient compliance with medical advice given by telephone. Am J Emerg Med. 2003;21(4):288–92.12898484
147 Lake R, Li L, Baysari M, . Capturing Accurate and Useful Information on Medication-Related Telenursing Triage Calls. Studies in Health Technology & Informatics. 2016;227:74–79.27440292
148 Langabeer JR, 2nd, Champagne-Langabeer T, Alqusairi D, . Cost-benefit analysis of telehealth in pre-hospital care. J Telemed Telecare. 2017;23(8):747–751.27913657
149 Larson-Dahn ML. Tel-eNurse Practice. Quality of care and patient outcomes. J Nurs Adm. 2001;31(3):145–52.11263064
150 Lattimer V, Turnbull J, Burgess A, . Effect of introduction of integrated out of hours care in England: observational study. BMJ. 2005;331(7508):81–4.16002882
151 Lattimer V, Sassi F, George S, . Cost analysis of nurse telephone consultation in out of hours primary care: evidence from a randomised controlled trial. BMJ. 2000;320(7241):1053–7.10764368
152 Leclerc BS, Dunnigan L, Cote H, . Callers’ ability to understand advice received from a telephone health-line service: comparison of self-reported and registered data. Health Serv Res. 2003;38(2):697–710.12785568
153 Leibowitz R, Day S, Dunt D. A systematic review of the effect of different models of after-hours primary medical care services on clinical outcome, medical workload, and patient and GP satisfaction. Fam Pract. 2003;20(3):311–7.12738701
154 Leng S, MacDougall M, McKinstry B. The acceptability to patients of video-consulting in general practice: semi-structured interviews in three diverse general practices. J Innov Health Inform. 2016;23(2):141.27869579
155 Leshem-Rubinow E, Assa EB, Shacham Y, . Expediting Time from Symptoms to Medical Contact Utilizing a Telemedicine Call Center. Telemed J E Health. 2015;21(10):801–7.26431259
156 Leutgeb R, Walker N, Remmen R, . On a European collaboration to identify organizational models, potential shortcomings and improvement options in out-of-hours primary health care. Eur J Gen Pract. 2014;20(3):233–7.24654834
157 Liederman EM, Lee JC, Baquero VH, . Patient-physician web messaging: The impact on message volume and satisfaction. J Gen Intern Med. 2005;20(1):52–57.15693928
158 Lin CT, Wittevrongel L, Moore L, . An internet-based patient-provider communication system: Randomized controlled trial. J Med Internet Res. 2005;7(4).
159 Ling LI, Georgiou A, Xiong J, . Healthdirect’s After Hours GP Helpline - A Survey of Patient Satisfaction with the Service and Compliance with Advice. Studies in Health Technology & Informatics. 2016;227:87–92.27440294
160 Loane M, Wootton R. A review of guidelines and standards for telemedicine. J Telemed Telecare. 2002;8(2):63–71.
161 Locatis C, Williamson D, Gould-Kabler C, . Comparing in-person, video, and telephonic medical interpretation. J Gen Intern Med. 2010;25(4):345–50.20107916
162 Lowes RL. Here, nurses take the calls that doctors hate. Med Econ. 1997;74(3):57–8, 60, 63–6.
163 Madlon-Kay DJ. Institution of a ‘no narcotics’ policy for after-hours telephone calls. J Fam Pract. 1991;33(1):92–4.2056295
164 Manuel J. Emergency department phone triage record. J Emerg Nurs. 1993;19(1):53.8437405
165 Marklund B, Strom M, Mansson J, . Computer-supported telephone nurse triage: an evaluation of medical quality and costs. J Nurs Manag. 2007;15(2):180–7.17352701
166 Marklund B, Koritz P, Bjorkander E, . How well do nurse-run telephone consultations and consultations in the surgery agree? Experience in Swedish primary health care. Br J Gen Pract. 1991;41(352):462–5.1807306
167 Marklund B, Bengtsson C, Blomkvist S, . Evaluation of the telephone advisory activity at Swedish primary health care centres. Fam Pract. 1990;7(3):184–9.2245888
168 Martin C, Fruin M. Telephone consultation for a “managed care” population. J Emerg Nurs. 1995;21(2):155–6.7776608
169 Martinsson J, Gustafsson S. Modeling the effects of telephone nursing on healthcare utilization. Int J Med Inform. 2018;113:98–105.29976474
170 Marvicsin DJ, Eagle MJ, Munro ML, . Lessons Learned From Examining After-Hours Call Patterns. Journal for Nurse Practitioners. 2015;11(2):233–239.
171 Maynard A. Primary care ideas. Entrepreneurial spirit. Health Serv J. 2004;114(5907):16–7.
172 Mayor S. Primary care telephone triage does not reduce workload, study finds. BMJ: British Medical Journal. 2014;349(7970):2–2.
173 McCarthy D. The virtual health economy: telemedicine and the supply of primary care physicians in rural America. Am J Law Med. 1995;21(1):111–30.7573080
174 McKenzie R. Consumer awareness, satisfaction, motivation and perceived benefits from using an after-hours GP helpline - A mixed methods study. Aust Fam Physician. 2016;45(7):512–7.27610436
175 McKenzie R, Dunt D, Yates A. Patient intention and self-reported compliance in relation to emergency department attendance after using an after hours GP helpline. Emerg Med Australas. 2016;28(5):538–43.27487992
176 McKenzie R, Williamson M, Roberts R. Who uses the ‘after hours GP helpline’? A profile of users of an after-hours primary care helpline. Aust Fam Physician. 2016;45(5):313–8.27166469
177 McKenzie R, Williamson M. The league of extraordinary generalists: a qualitative study of professional identity and perceptions of role of GPs working on a national after hours helpline in Australia. BMC Health Serv Res. 2016;16:142.27101878
178 McKinstry B, Walker J, Campbell C, . Telephone consultations may be useful for people who request same-day appointments, but do not reduce workload. Evidence-Based Healthcare. 2002;6(4):154–155.
179 McNeil C. Skilled telephone triage programs streamline symptom management. Oncology (Williston Park). 2007;21(2 Suppl Nurse Ed):42–4.17474363
180 McNicholas JE. TeleHealth in the Modern Era of Military Medical Consultation. Mil Med. 2018;183(5-6):110–112.29546338
181 Meng D, Palen TE, Tsai J, . Association between secure patient-clinician email and clinical services utilisation in a US integrated health system: a retrospective cohort study. BMJ Open. 2015;5(11):e009557.
182 Midtbo V, Raknes G, Hunskaar S. Telephone counselling by nurses in Norwegian primary care out-of-hours services: a cross-sectional study. BMC Fam Pract. 2017;18(1):84.28874124
183 Moffatt JJ, Eley DS. Barriers to the up-take of telemedicine in Australia-a view from providers. Rural Remote Health. 2011;11(2):1581.21385004
184 Mohammed MA, Clements G, Edwards E, . Factors which influence the length of an out-of-hours telephone consultation in primary care: a retrospective database study. BMC Health Serv Res. 2012;12:430.23181707
185 Moll van Charante EP, ter Riet G, Drost S, . Nurse telephone triage in out-of-hours GP practice: determinants of independent advice and return consultation. BMC Fam Pract. 2006;7:74.17163984
186 Moll van Charante E, Giesen P, Mokkink H, . Patient satisfaction with large-scale out-of-hours primary health care in The Netherlands: development of a postal questionnaire. Fam Pract. 2006;23(4):437–43.16641129
187 Monsuez JJ, Charniot JC, Tine S, . Phones during consultation. Int J Cardiol. 2009;133(1):113.18158187
188 Montalto M, Dunt DR, Day SE, . Testing the safety of after-hours telephone triage: patient simulations with validated scenarios. Australasian Emergency Nursing Journal. 2010;13(1-2):7–16.
189 Moore JD, Saywell RM, Thakker N, . An analysis of patient compliance with nurse recommendations from an after-hours call center. Am J Manag Care. 2002;8(4):343–51.11950129
190 Moriarty H, McLeod D, Dowell A. Mystery shopping in health service evaluation. Br J Gen Pract. 2003;53(497):942–6.14960218
191 Morimura N, Ishikawa J, Kitsuta Y, . An analysis of spoken language expression during simulated emergency call triage. Eur J Emerg Med. 2005;12(2):72–7.15756082
192 Morrow J. The telephone. Emergency Medicine Journal. 2005:8–8.15611534
193 Moth G, Huibers L, Christensen MB, . Drug prescription by telephone consultation in Danish out-of-hours primary care: a population-based study of frequency and associations with clinical severity and diagnosis. BMC Fam Pract. 2014;15:142.25139205
194 Moth G, Huibers L, Vedsted P. From Doctor to Nurse Triage in the Danish Out-of-Hours Primary Care Service: Simulated Effects on Costs. Int J Family Med. 2013;2013:987834.24194984
195 Mounce LTA, Barry HE, Calitri R, . Establishing the validity of English GP Patient Survey items evaluating out-of-hours care. BMJ Quality and Safety. 2016;25(11):842–850.
196 Munro J, O’Cathain A, Knowles E, . Evaluation of NHS Direct “referral" to community pharmacists. International Journal of Pharmacy Practice. 2003;11(1):1–9.
197 Murphy M, Risser N. NP abstracts. Telephone health care. Nurse Practitioner. 2000;25(2):87–87.
198 Narasimha S, Madathil KC, Agnisarman S, . Designing Telemedicine Systems for Geriatric Patients: A Review of the Usability Studies. Telemed J E Health. 2017;23(6):459–472.27875667
199 Nemes J. Plugging into technology brings hearing care to developing nations. Hearing Journal. 2011;64(9):21–26.
200 Newbould J, Abel G, Ball S, . Evaluation of telephone first approach to demand management in English general practice: observational study. BMJ. 2017;358:j4197.28954741
201 Newton S. Tips on performing telephone triage. Clin J Oncol Nurs. 2006;10(4):524–526.
202 Niemann S, Meer A, Simonin C, . Medical telephone triage and patient behaviour: How do they compare? Swiss Med Wkly. 2004;134(9-10):126–31.15106022
203 Niv Y, Itskoviz D, Cohen M, . The Utility of Failure Modes and Effects Analysis of Consultations in a Tertiary, Academic, Medical Center. Qual Manag Health Care. 2018;27(2):69–73.29596266
204 North F, Richards DD, Bremseth KA, . Clinical decision support improves quality of telephone triage documentation-an analysis of triage documentation before and after computerized clinical decision support. BMC Med Inform Decis Mak. 2014;14:20.24645674
205 O’Cathain A, Knowles E, Turner J, . Acceptability of NHS 111 the telephone service for urgent health care: cross sectional postal survey of users’ views. Fam Pract. 2014;31(2):193–200.24334420
206 O’Cathain A, Webber E, Nicholl J, . NHS Direct: consistency of triage outcomes. Emerg Med J. 2003;20(3):289–92.12748157
207 Olesen F, Jolleys JV. Out of hours service: the Danish solution examined. BMJ. 1994;309(6969):1624–6.7819945
208 O’Malley AS, Samuel D, Bond AM, . After-hours care and its coordination with primary care in the US J Gen Intern Med. 2012;27(11):1406–15.22653379
209 Ong RS, Post J, van Rooij H, . Call-duration and triage decisions in out of hours cooperatives with and without the use of an expert system. BMC Fam Pract. 2008;9:11.18271970
210 Onubogu UD, Earp JK. Telephone Nursing Practice: How Do Telenurses Perceive Their Role? Journal of Best Practices in Health Professions Diversity: Education, Research & Policy. 2013;6(1):891–902.
211 Owens SJ. Telephone Triage in Ophthalmology Settings. Insight: The Journal of the American Society of Ophthalmic Registered Nurses. 2017;42(3):26–29.
212 Palma E, Antonaci D, Colì A, . Analysis of emergency medical services triage and dispatch errors by registered nurses in Italy. Journal of emergency nursing: JEN : official publication of the Emergency Department Nurses Association. 2014;40(5):476–483.24746868
213 Pancer Z, Moore M, Wenham JT, . The challenge of generalist care in remote Australia: Beyond aeromedical retrieval. Australian Journal of Rural Health. 2018;26(3):188–193.29115700
214 Philips H, Van Bergen J, Huibers L, . Agreement on urgency assessment between secretaries and general practitioners: an observational study in out-of-hours general practice service in Belgium. Acta Clin Belg. 2015;70(5):309–14.25819448
215 Poole R, Gamper A, Porter A, . Exploring patients’ self-reported experiences of out-of-hours primary care and their suggestions for improvement: a qualitative study. Fam Pract. 2011;28(2):210–9.21059702
216 Pooley CG, Briggs J, Gatrell T, . Contacting your GP when the surgery is closed: Issues of location and access. Health and Place. 2003;9(1):23–32.12609470
217 Pope C, Turnbull J, Jones J, . Has the NHS 111 urgent care telephone service been a success? Case study and secondary data analysis in England. BMJ Open. 2017;7(5):e014815.
218 Posocco A, Scapinello MP, De Ronch I, . Role of out of hours primary care service in limiting inappropriate access to emergency department. Intern Emerg Med. 2018;13(4):549–555.28547207
219 Proctor JH, Hirshberg AJ, Kazzi AA, . Providing telephone advice from the emergency department. Ann Emerg Med. 2002;40(2):217–9.12140502
220 Quallich SA. Caller ID: the art of telephone triage. Urol Nurs. 2003;23(3):229–30, 220.12861744
221 Reisinger PB. Experiences of critical care nurses in telephone triage positions. Dimens Crit Care Nurs. 1998;17(1):20–7.9481270
222 Richards D, Tawfik J. Introducing nurse telephone triage into primary care. Nurs Stand. 2000;15(10):42–5.
223 Ritter LA, Robinette TR, Cofano J. Evaluation of a statewide telemedicine program. Californian Journal of Health Promotion. 2010;8(1):1–9.25750596
224 Roberts E, Mays N. Can primary care and community-based models of emergency care substitute for the hospital accident and emergency (A & E) department? Health Policy. 1998;44(3):191–214.10182293
225 Roberts J. The telephone consultation process: part II. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2007(36):76–80.
226 Roberts J. Telephone consultation and risk management. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2007(35):75–77.
227 Robinson DL, Anderson MM, Acheson PM. Telephone advice: lessons learned and considerations for starting programs. J Emerg Nurs. 1996;22(5):409–15.8997966
228 Rodway H. Consultation call. Occupational Health. 2013;65(10):31–34.
229 Roing M, Holmstrom IK. Malpractice claims in Swedish telenursing: lessons learned from interviews with telenurses and managers. Nurs Res. 2015;64(1):35–43.25502059
230 Rortveit S, Meland E, Hunskaar S. Changes of triage by GPs during the course of prehospital emergency situations in a Norwegian rural community. Scand J Trauma Resusc Emerg Med. 2013;21:89.24354953
231 Rosenblatt E. Telephone triage. A common sense approach. Rn. 2001;64(3):suppl 2-3.
232 Rutenberg CD. Telephone triage. Am J Nurs. 2000;100(3):77–81.
233 Rutenberg CD. What do we really KNOW about telephone triage? J Emerg Nurs. 2000;26(1):76–8.10657806
234 Rutenberg C. How to recognize life-threatening emergencies over the phone. Nursing. 2008;38(2):56hn1–56hn4.18580670
235 Sagrillo DP, Kuns S. Journal club. Telephone triage for nurses. Plastic Surgical Nursing. 2002;22(1):38–41.
236 Sakurai A, Morimura N, Takeda M, . A retrospective quality assessment of the 7119 call triage system in Tokyo - telephone triage for non-ambulance cases. J Telemed Telecare. 2014;20(5):233–238.24829258
237 Salisbury C, Burgess A, Lattimer V, . Developing a standard short questionnaire for the assessment of patient satisfaction with out-of-hours primary care. Fam Pract. 2005;22(5):560–9.15964865
238 Salisbury C, Trivella M, Bruster S. Demand for and supply of out of hours care from general practitioners in England and Scotland: observational study based on routinely collected data. BMJ. 2000;320(7235):618–21.10698882
239 Salisbury C. Observational study of a general practice out of hours cooperative: measures of activity. BMJ. 1997;314(7075):182–6.9022433
240 Salk ED, Schriger DL, Hubbell KA, . Effect of visual cues, vital signs, and protocols on triage: a prospective randomized crossover trial. Ann Emerg Med. 1998;32(6):655–64.9832660
241 Salman OH, Rasid MF, Saripan MI, . Multi-sources data fusion framework for remote triage prioritization in telehealth. J Med Syst. 2014;38(9):103.25047520
242 Sanderson S, Anderson D, Dugan L. Patient emergency planning & teletriage: the ACH reduction connection. Home Health Care Management & Practice. 2008;20(2):125–134.
243 Sands N, Elsom S, Gerdtz M, . Identifying the core competencies of mental health telephone triage. J Clin Nurs. 2013;22(21-22):3203–16.22860919
244 Sandvik H, Hunskaar S. Frequent attenders at primary care out-of-hours services: a registry-based observational study in Norway. BMC Health Serv Res. 2018;18(1):492.29940934
245 Sapien R, Brillman JC. Telephone triage. Ann Emerg Med. 2000;35(1):99–100.
246 Schlachta-Fairchild L, Varghese SB, Deickman A, . Telehealth and telenursing are live: APN policy and practice implications. Journal for Nurse Practitioners. 2010;6(2):98–106.
247 Schoenfeld AJ, Davies JM, Marafino BJ, . Variation in quality of urgent health care provided during commercial virtual visits. JAMA Internal Medicine. 2016;176(5):635–642.27042813
248 Scott-Jones J, Lawrenson R, Maxwell N. Sharing after hours care in a rural New Zealand community-a service utilization survey. Rural Remote Health. 2008;8(4):1024.18999904
249 Shani M, Wang HHX, Wong SYS, . Out of hours international primary care snapshots: Israel and China. British Journal of General Practice. 2015;65(634):250–251.25918318
250 Shekelle P, Roland M. Nurse-led telephone-advice lines. Lancet. 1999;354(9173):88–9.10408478
251 Simonsen-Anderson S. Safe and sound. Nurs Manage. 2002;33(6):41–3.
252 Simpson RG, Graham D, Martin K. Analysis of out of hours telephone consultation at the medical reception station Sennelager, British Forces Germany. J R Army Med Corps. 2000;146(1):28–30.15241981
253 Singh K, Warnock C. Assessing the value of a nurse.led telephone advice and triage service. Cancer Nursing Practice. 2013;12(4):30–35.
254 Skorin-Kapov L, Matijasevic M. Analysis of QoS requirements for e-Health services and mapping to evolved packet system QoS classes. International Journal of Telemedicine and Applications. 2010.
255 Smith H, Lattimer V, George S. General practitioners’ perceptions of the appropriateness and inappropriateness of out-of-hours calls. British Journal of General Practice. 2001;51(465):270–275.11458478
256 Smits M, Keizer E, Ram P, . Development and testing of the KERNset: an instrument to assess the quality of telephone triage in out-of-hours primary care services. BMC Health Serv Res. 2017;17(1):798.29197376
257 Smits M, Rutten M, Keizer E, . The Development and Performance of After-Hours Primary Care in the Netherlands: A Narrative Review. Ann Intern Med. 2017;166(10):737–742.28418455
258 Smits M, Hanssen S, Huibers L, . Telephone triage in general practices: A written case scenario study in the Netherlands. Scand J Prim Health Care. 2016;34(1):28–36.26893132
259 Smitsa M, Hanssena S, Huibersa L, . Telephone triage in general practices: A written case scenario study in the Netherlands. Scand J Prim Health Care. 2016;34(1):28–36.26893132
260 Snooks H, Peconi J, Munro J, . An evaluation of the appropriateness of advice and healthcare contacts made following calls to NHS Direct Wales. BMC Health Serv Res. 2009;9:178.19793398
261 Spence D. Out of hours care: a call for continuity. BMJ. 2012;344:e279.22236600
262 Sprivulis P, Carey M, Rouse I. Compliance with advice and appropriateness of emergency presentation following contact with the HealthDirect telephone triage service. Emerg Med Australas. 2004;16(1):35–40.15239753
263 Srámek M, Post W, Koster RW. Telephone triage of cardiac emergency calls by dispatchers: a prospective study of 1386 emergency calls. Br Heart J. 1994;71(5):440–445.8011407
264 Stern G. Integrated Call System Bridges Gap between HTM and IT. Biomed Instrum Technol. 2017;51(3):265–268.28530865
265 Storhaug HC, Mead SB, Steinsbekk A. A qualitative study of employees’ opinions on establishing a generic call-centre. BMC Fam Pract. 2017;18(1):90.29041908
266 Stowe S, Harding S. Telecare, telehealth and telemedicine. European Geriatric Medicine. 2010;1(3):193–197.
267 Ström M, Baigi A, Hildingh C, . Patient care encounters with the MCHL: A questionnaire study. Scand J Caring Sci. 2011;25(3):517–524.21338380
268 Swage T, Longman H. Hanging on the telephone. Health Serv J. 2013;123(6364):24–5.
269 Thompson F, George S, Lattimer V, . Overnight calls in primary care: randomised controlled trial of management using nurse telephone consultation. BMJ. 1999;319(7222):1408.10574857
270 Tran DT, Gibson A, Randall D, . Compliance with telephone triage advice among adults aged 45 years and older: an Australian data linkage study. BMC Health Serv Res. 2017;17(1):512.28764695
271 Tranberg M, Vedsted P, Bech BH, . Factors associated with low patient satisfaction in out-of-hours primary care in Denmark - a population-based cross-sectional study. BMC Fam Pract. 2018;19(1):15.29325520
272 Tuckson RV, Edmunds M, Hodgkins ML. Telehealth. New England Journal of Medicine. 2017;377(16):1585–1592.29045204
273 Tuden DS, Borycki EM, Kushniruk AW. Clinical Simulation: Evaluating the Usability of a Health Information System in a Telenurse Call Centre. Stud Health Technol Inform. 2017;234:340–345.28186065
274 Turner VF, Bentley PJ, Hodgson SA, . Telephone triage in Western Australia. Med J Aust. 2002;176(3):100–3.11936303
275 van der Biezen M, Wensing M, van der Burgt R, . Towards an optimal composition of general practitioners and nurse practitioners in out-of-hours primary care teams: a quasi-experimental study. BMJ Open. 2017;7(5):e015509.
276 Van Der Biezen M, Adang E, Van Der Burgt R, . The impact of substituting general practitioners with nurse practitioners on resource use, production and health-care costs during out-of-hours: a quasi-experimental study. BMC Fam Pract. 2016;17(1):132.27619968
277 van Galen LS, Car J. Telephone consultations. BMJ. 2018;360:k1047.29599197
278 van Ierland Y, van Veen M, Huibers L, . Validity of telephone and physical triage in emergency care: the Netherlands Triage System. Fam Pract. 2011;28(3):334–41.21106645
279 van Uden CJ, Giesen PH, Metsemakers JF, . Development of out-of-hours primary care by general practitioners (GPs) in The Netherlands: from small-call rotations to large-scale GP cooperatives. Fam Med. 2006;38(8):565–9.16944387
280 Verzantvoort NCM, Teunis T, Verheij TJM, . Self-triage for acute primary care via a smartphone application: Practical, safe and efficient? PLoS ONE. 2018;13(6).
281 Vitacca M, Mazzú M, Scalvini S. Socio-technical and organizational challenges to wider e-Health implementation. Chron Respir Dis. 2009;6(2):91–97.19411570
282 Wallace P, Haines A, Harrison R, . Design and performance of a multi-centre randomised controlled trial and economic evaluation of joint tele-consultations [ISRCTN54264250]. BMC Fam Pract. 2002;3:1.11835692
283 Warren FC, Abel G, Lyratzopoulos G, . Characteristics of service users and provider organisations associated with experience of out of hours general practitioner care in England: Population based cross sectional postal questionnaire survey. BMJ (Online). 2015;350.
284 Wheeler SQ, Greenberg ME, Mahlmeister L, . Safety of clinical and non-clinical decision makers in telephone triage: a narrative review. J Telemed Telecare. 2015;21(6):305–22.25761468
285 Wheeler S. Telephone triage: SAVED by the form. Nursing. 2000;30(11):54–5.
286 Willson B. Telephone advice. Nurs BC. 2003;35(3):27–8.13677715
287 Wootton R. Recent advances: Telemedicine. BMJ. 2001;323(7312):557–60.11546704
288 Wouters L. Telephone triage on the out-of-hours GP service. Huisarts en Wetenschap. 2016;59(7):306.
289 Youssef GG, Underhill TJ, Tovey C. Referral to the accident and emergency department following the use of community alarms. J Accid Emerg Med. 2000;17(5):348–50.11005406
290 Zummo ML. Exploring web-mediated communication: A genre-based linguistic study for new patterns of doctor-patient interaction in online environment. Communication & Medicine (Equinox Publishing Group). 2015;12(2/3):187–198.