# APPENDIX C Study Characteristics Tables

## KQ 1 Studies

Study; Country; # Enrolled; # Arms; Relevant KQ; (Companion Papers) | Key Components (Staff, Mode, Protocol, Hours) | Eligibility | Mean Age (SD); % Female; % Race; Top 3 Health Issues; Insurance Type | Reported Outcomes Timing; Primary Outcome | Risk of Bias for Objective and Patient-Reported Outcomes
RCT: Individual randomization
McKinstry, 2002^42^; Scotland; N=388 patients; 2 arms; KQs 1, 3 | MD; Telephone; Protocol NR; Regular hours | Patients of 2 general medical practices calling to request a same-day appointment | Age: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: National Health Service | Outcomes:; - Patient satisfaction; - Utilization:; - ED visit; - Primary care visit; Timing: Study based on single point of telephone contact; use of service 2 weeks after randomization; Primary outcome: Physician time spent on telephone advice vs face-to-face care | Objective: Low; Patient reported: High
RCT: Cluster randomization
Campbell, 2014^38^; ESTEEM Trial; UK; N=20,990 patients; 3 arms; KQs 1, 2, 3; Primary study for KQ 2: Campbell, 2015^92^; (Holt, 2016^93^ Warren, 2015^94^ Calitri, 2015^95^ Murdoch, 2015^96^ Varley, 2016^97^ Holt, 2016^98^ Anonymous, 2014^99^ Mayor, 2014^100^) | (1) MD Telephone Protocol: Stour access system Hours NR; (2) Nurse (NP, RN) Telephone Protocol: Plain Healthcare Odyssey Patient Access Hours NR | Practices in 1 of 4 UK “centers” linked to university medical school; recruitment run through a primary care research network without an existing remote triage system (defined as a telephone-based system to manage more than 75% of same-day requests) | [underlined: MD Triage:]; Age: 43.08 (24.32); Female: 59.54%; White: 56.03%; Black: <1%; Hispanic: NA; Asian: 1.15%; Other: <1%; Top 3: NR; Insurance type: NR; [underlined: Nurse Triage:]; Age: 41.5 (25.2); Female: 60%; White: 51.0%; Black: <1%; Hispanic: NA; Asian: 1.57%; Other: <1%; Top 3: NR; Insurance type: National Health Service | Outcomes:; - Patient satisfaction; - Patient safety; - Deaths; - Hospitalization; - ED visit; - Total cost; - Utilization:; - ED visit; - Primary care visit; Timing: 28 days; Primary outcome: Workload - total number of primary care contracts taking place in 28 days after index appointment request | Objective: Unclear Patient reported: Unclear
Cragg, 1997^44^; UK; N=2152 patients; 2 arms; KQs 1, 2, 3; (McKinley, 1997^101^) | MD; Telephone; Protocol NR; After hours | Patients at 1 of 14 practices in Manchester, Salford, Stockport, or Leicester who were resident in that practice for more than 2 weeks and placed an out-of-hours phone call to the practice during the study period | Age: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: National Health Service | Outcomes:; - Call resolution; - On-call resolution; - Primary care visit; - ED visit; - Patient satisfaction; - Utilization:; - Primary care visit; Timing: 24-120 hours after call; Primary outcome: NR | Overall-objective: High; Overall-patient reported: High
Lattimer, 1998^43^; UK; N=14492 calls; 2 arms; KQs 1, 2, 3; (Lattimer, 2000^102^ Anonymous, 2000^103^) | NP, unspecified/admin, receptionist; Telephone; Protocol: telephone advice system; After hours | Patients registered with any of the 19 GP practices in South Wiltshire | Age: NR; Female: 52%; Race: NR; Top 3: NR; Insurance type: National Health Service | Outcomes:; - Call resolution; - On-call resolution; - Primary care visit; - ED visit; - Utilization; - ED visit; - Patient safety; Timing: 12 months; Primary outcome: Safety and effectiveness of intervention | Overall-objective: Low; Overall-patient reported: NA
Richards, 2004^40^; England; N=4718 patients; 2 arms; KQs 1, 2, 3 | NP unspecified; Telephone; Protocol: documented; Regular hours | Patients part of a general practice in York, England making a phone call to that practice for a same-day appointment | Age: 7 age categories; Female: 62.7%; Race: NR; Top 3:; - Respiratory system: 38.5%; - Digestive system: 14.5%; - Musculoskeletal: 13.9%; Insurance type: National Health Service | Outcomes:; - Call resolution; - On-call resolution; - Primary care visit; - Utilization:; - ED visit; - Primary care visit; - Total cost; Timing: Index consultations; follow-up care 1 month after index; Primary outcome: Type of consultation after “final point of contact” | Overall-objective: Low; Overall-patient reported: NA
Controlled before-after
Knowles, 2016^37^; England; N=2237 patients; 4 arms; KQs 1, 3; (Southard, 2014^104^ O’Cathain, 2014^105^) | Nonclinical call handlers; Telephone; NHS Pathways software; Regular and after hours | Partitioned by locations served by NHS trusts; English language; age ≥16 for respondent but user of service could be a child; other: recent user of urgent care | Age: 5 age categories; [underlined: NHS 111 before arm]; Female: 45.9%; White: 86.2%; Black: NA; Hispanic: NA; Asian: NA; Other: 13.7%; [underlined: NHS 111 after arm]; Female: 51.2%; White: 86.7%; Black: NA; Hispanic: NA; Asian: NA; Other: 13.3%; Top 3: NR; Insurance type: National Health Service | Outcomes:; - Patient satisfaction; Timing: 9 or 12 months; Primary outcome: Change in satisfaction with telephone triage 9 months (or 12 months) after the launch of NHS 111 | Overall-objective: NA; Overall-patient reported: High
Munro, 2000^45^; UK; N=68,500 calls; 1 arm; KQs 1, 3 | NP; Telephone; Protocol: NHS Clinical Assessment System; Regular and after hours | Population receiving health care in Preston and Corley, Milton Keynes, and Northumbria regions in the United Kingdom | Age: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Outcomes:; - Utilization; - ED visit; - Primary care visit; Timing: 24 months; Primary outcome: Changes in trends in use of health care system after introduction of nurse-led triage | Overall-objective: High; Overall-patient reported: NA
Turner, 2013^39^; England; N=1,802,000 calls; 2 arms; KQs 1, 2, 3; (Southard, 2014^104^ O’Cathain, 2014^105^) | NP, unspecified/admin receptionist; Telephone; Protocol: NHS Pathways Assessment System; Regular and after hours | Community user in different geographic areas placing a triage telephone call; no N reported for control arm (NHS Direct); different cities/regions compared | Age: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: National Health Service | Outcomes:; - Utilization; - ED visit; - Primary care visit; Timing: 12 months; Primary outcome: Changes in use of emergency and urgent care services | Overall-objective: Unclear; Overall-patient reported: NA
Interrupted time series
Richards, 2002^41^; UK; N=4685 patients; 2 arms; KQs 1, 2, 3; (Richards, 2004^106^) | RN; Telephone; Protocol: Internally developed; Regular hours | Consecutive patients in 1 of 3 practices around York, England, who called requesting a same-day appointment; member of general practice group | Age: 0 to ≥75; Female: 61.3%; Race: NR; Top 3:; - Respiratory, 37.8%; - Dermatological, 15.2%; - Musculoskeletal, 13.3%; Insurance type: National Health Service | Outcomes:; - Call resolution; - On call resolution; - Primary care visit; - Utilization:; - ED visit; - Primary care visit; - Total cost; Timing: Time of call through 1 month thereafter; Primary outcome: NR | Overall ROB rating for interrupted time series: Low

Abbreviations: CDSS=clinical decision support software/system; CeCC=CareEnhance Call Centre software; ED=emergency department; GP=general practitioner; MD=medical doctor; NA=not applicable; NHS=National Health Service; NP=nurse practitioner; NR=not reported; PEE=planning, execution, evaluation (phases); PPT=people, process, technology (aspects); ROB=risk of bias; SD=standard deviation

## KQ 2 Studies

Study; Country; # Enrolled; Study Design; (Companion) | Key Components (Staff, Mode, Protocol, Hours) | Eligibility | Mean Age (SD); % Adult; % Female; % Race; Top 3 Health Issues; Insurance Type | Outcome Description; Level (PEE); Aspect (PPT) | Risk of Bias
Qualitative studies
Banks, 2018^81^; UK; 23; Qualitative | MDs, NPs, Admins, Practice Managers Internet-based eConsult; Hours NR | Practice staff including reception and administrative staff, practice managers, and GPs from 6 practices in the west of England. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Evaluation: Process; Evaluation: People | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Derkx, 2007^80^; Netherlands; 8; Qualitative | Focus group members (patients, call handlers, GPs, management); Telephone; Protocol NR; After hours | Patients were members of patient groups; call handlers worked at after-hours call centers as supervisors or call handlers; GPs worked at after-hours centers and were involved in ensuring quality of care; and members of the management team were involved with general issues of management at after-hours centers. | Age: NR; Adult: 100%; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Evaluation: People | Appropriate approach? Yes; Adequate data collection? Can’t tell; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Eccles, 2015^62^; UK; 55; Qualitative | MD, call handlers; Telephone; Internally developed protocol; After hours | Patients who called Cardiff and Vale after-hours service both before and after an “expert triage” service was implemented in April 2013. GP triage practitioners who practiced under either the “previous” or “expert triage” models or both. | Age: NR; Adult: 100%; Female: NR; Race: NR; Top 3: NR; Insurance type: National Health Service | Planning: People; Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Edwards, 1998^67^; UK; 8; Qualitative | Nurse; Telephone; Simulated calls for triage; Hours NR | Qualified nurses working in community hospitals with walk-in minor injury service that also handled phone inquiries. | Age: 23-50; Adult: 100%; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: Process; Execution: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Foster, 1999^63^; UK; 38; Qualitative | MD; Telephone; Protocol NR; After hours | GPs recruited from one health authority in south London. | Mean Age: 42; Adult: 100%; Female: 71%; Race: NR; Top 3: NR; Insurance type: NR | Planning: People; Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Gamst-Jensen, 2017^68^; Denmark; 19; Mixed methods | Nurse, MD; Telephone; Internally developed protocol; After hours | Patients who called the after-hours hotline in Copenhagen. | Age: <1 to 79; Adult: 84%; Female: 58%; Race: NR; Top 3: abdominal pain; Insurance type: NR | Execution: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Greatbatch, 2005^82^; UK; 60; Qualitative | Nurse, call handlers; Telephone; NHS Direct computerized clinical assessment system (CAS); Regular hours and after hours | 60 calls were selected from one site within NHS. No specific criteria identified. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: Technology; Evaluation: Technology | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Holmström, 2007^76^; Sweden; 12; Qualitative; (Ernesater, 2009^107^) | Nurse; Telephone; Protocol NR; Regular hours | Nurses were recruited from 1 call center in mid-Sweden between 2004-2005. | Age: 35-63; Adult: 100%; Female: 0%; Race: NR; Top 3: NR; Insurance type: NR | Planning: People; Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Holmström, 2016^75^; Sweden; 10; Qualitative | Nurse; Telephone; Protocol NR; Regular hours | Inclusion criteria were that the participants were older than 65 and have experience calling telephone advise nursing services seeking advice for a health-related problem. Patients were excluded who only called to make an appointment to see a clinician. | Age: 68-95; Adult: 100%; Female: 60%; Race: NR; Top 3: NR; Insurance type: NR | Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Lopriore, 2017^83^; Australia; 196; Qualitative | RN; Telephone; Computer decision support software and HealthCare Direct policy; Hours NR | Patients calling in on the triage health care phone line. | Age: NR; Adult: 100%; Female: 100%; Race: NR; Top 3: NR; Insurance type: National health insurance | Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
O’Cathain, 2004^79^; UK; 24; Mixed methods; (O’Cathain, 2004^108^) | RN; Telephone; 3 different decision support programs used by the interviewed nurses; Regular hours, after hours | Triage nurse in one of 12 sites for NHS Direct for the interview (qualitative) portion or in one of 14 sites and who had received more than 10 triage calls for the abstracted (quantitative) portion. | Age: NR; Adult: 100%; Female: 90%; Race: NR; Top 3: NR; Insurance type: NR | Planning: People; Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Pettinari, 2001^69^; UK; 14; Qualitative | Nurse; Telephone; NHS CDSS “Clinical Decision Support Software”; Regular hours, after-hours | None explicitly stated | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Execution: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Pope, 2013^72^; UK; 64; Qualitative | Call handlers; Telephone; Clinical Decision Support (CDS); Regular hours, after hours | Call handlers were purposely sampled. Stakeholders, system developers, corporate/operational managers were also considered. Sampled participants worked in 1 of 3 settings within the NHS: for 999 emergency care, a GP after-hours urgent care service, or a single point of access service. | Age: NR; Adult: 100%; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Execution: Technology; Evaluation: Technology | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Purc-Stephenson, 2010^64^; Multiple 16 studies Meta-ethnography | Nurse; Telephone; Protocol NR; Hours NR | Studies meeting following criteria: include an evaluation of telephone triage and advice; use qualitative methodology; include nurses in the sample; provide primary-care services. Excluded reviews or discussion papers, and studies in which telephone service was for specialized services, chronic conditions, or mental health. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: People; Planning: Process; Execution: Process | Overall ROB rating: Good
Richards, 2007^74^; UK; 27; Qualitative | MD, nurse, unspecified, admin, paramedic; Telephone; Protocol used (no information); After-hours | Users of after-hours primary care services in 3 regions in England over a 2-week period, with sampling strategy to include heterogeneity in terms of affluence, deprivation, and ethnic diversity, and equal numbers of service users from each area, parents of children aged 11 or younger and people in the age groups 17-49 and 50 plus, and individuals receiving different management options (telephone advice, treatment center, or home visit).; Exclusions: ages 12-16; person too unwell to participate in focus group/interview (eg, end-stage terminal illness, recent hospital admission, nursing home resident); contact details omitted; person flagged on system as aggressive or violent or and requiring special procedures. | Age: 55.4; Adult: 74%; Female: 48; Race:; White: 96%; Black: 4%; Top 3: NR; Insurance type: NR | Planning: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Roberts, 2009^77^; UK; 35; Qualitative | Nurse; Telephone; Protocol NR; Regular hours, after hours | Stakeholders=senior level individuals working on the design and implementation of NHS24; Partners=individuals with responsibility for the delivery of care within one of the partner organizations. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: Process; Execution: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Röing, 2015^65^; Sweden; 11; Qualitative | RN, Call Managers; Telephone; Decision Support Tool (DST); Regular hours, after hours | Telenurses involved in one of 33 malpractice claims filed between 2003-2010 or managers of one of the 23 call centers throughout Sweden for the national healthcare hotline. | | Planning: Process; Evaluation: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Tariq, 2017^73^; Australia; 9; Mixed methods | Nurse; Telephone; CeCC; Regular hours, after hours | The national remote triage system, Healthdirect Australia, assisted in the identification of the nine nurses interviewed about the usability of the CeCC decision support system. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: Technology | Appropriate approach? Yes; Adequate data collection? Can’t tell; Findings derived from data? Can’t tell; Results substantiated by data? Yes; Coherence between data and interpretation? Can’t tell
Timpka, 1990^70^; Sweden; 5; Qualitative | Nurse; Telephone; Protocol NR; Hours NR | Eligible nurses were those who were receptionist nurses at the only HC in town. No other eligibility criteria were provided. | Age: 37; Adult: 100%; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Execution: Process | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Turnbull, 2012^78^; UK; 61; Mixed methods | NR; Telephone; CDSS; Hours NR | Method 1 Interviews: purposive sample of call-handlers and “stakeholders.”; Method 2 Observation: 491 hours.; Method 3 Survey: all call-handlers. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: People | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Turnbull, 2017^71^; UK; 47; Organizational case study (Turnbull, 2014^109^) | MD, RN, call advisers, unspecified/admin; Telephone; NHS Pathways; Regular hours, after hours | Employee at one of 5 NHS sites performing 111 services during 2011-12. | Age: NR; Adult: 100%; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Planning: People; Execution: Process; Planning: Technology | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Yes; Results substantiated by data? Yes; Coherence between data and interpretation? Yes
Wahlburg, 2018^61^; Sweden; 24; Qualitative (Bjorkman, 2017^110^) | Nurse; Telephone; CDSS; Hours NR | Worked in 1 of 6 chosen current call center for at least 6 months at the time of the interview. | Age: 55 (1.7); Adult: 100%; Female: 100%; Race: NR; Top 3: NR; Insurance type: NR | Planning: People; Planning: Process; Planning: Technology | Appropriate approach? Yes; Adequate data collection? Yes; Findings derived from data? Can’t tell; Results substantiated by data? Yes; Coherence between data and interpretation? Can’t tell
Systematic reviews
Blank, 2012^66^; Multiple 54 papers | MD, Nurse, Lay operator; Telephone; Protocol NR; Regular hours, after hours | This systematic review included studies about telephone triage. Twenty-six studies reported appropriateness of triage decisions and 26 papers reported on compliance with triage decision. Two studies reported both. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Execution: People; Evaluation: People; Execution: Process; Evaluation: Process | Overall ROB: Poor
Bunn, 2004^21^; NR; 9 studies | NR; Telephone; Protocol NR; Hours NR | Systematic review assessed the effects of telephone triage on safety, service usage, and patient satisfaction and compare telephone triage by different health care professionals. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Evaluation: Process; Evaluation: Technology | Overall ROB: Good
Carrasqueiro, 2011^36^; Multiple 55 studies | NR; Telephone; Protocol NR; Hours NR | This systematic review included studies on telephone triage to review evaluation studies and compile methodologies and metrics used as well as compare results. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Evaluation: Process | Overall ROB: Poor
Lake, 2017^23^; Multiple 10 systematic reviews | MD, Nurse, Admin/receptionist, Health assistant; Telephone; Protocol varies; Regular hours, after hours | Overview of systematic reviews focused on telephone-based triage and advice services; available in English; published since 1990; not targeting specific condition, population, medical specialty, or chronic conditions; and not related to general health education. | Age: NR; Adult: NR; Female: NR; Race: NR; Top 3: NR; Insurance type: NR | Execution: People; Evaluation: Process; Execution: Technology | Overall ROB: Fair

Abbreviations: CDSS=clinical decision support software/system; CeCC=CareEnhance Call Centre software; GP=general practitioner; MD=medical doctor; NHS=National Health Service; NP=nurse practitioner; NR=not reported; PEE=planning, execution, evaluation (phases); PPT=people, process, technology (aspects); ROB=risk of bias; SD=standard deviation