# APPENDIX B Intervention Characteristics Tables

For full study citations in this appendix, please refer to the report’s main reference list.

## KQ 1 Studies

Study; # Enrolled | Comparison Type; Description of Triage System | Type/Number of Professionals^a^; Dedicated Staff for Triage?^b^; Access to Medical Records? | Co-located Staff?; Special Training? | Decision Support Protocol^c^; Scope of Practice Described?^d^; Handoff to PCP?^e^ | Mode of Delivery; Hours of Operation; Caller Identified?^f^
RCTs (Individual and Cluster)
Campbell, 2014^38^; N=20990 patients | Comparison: Mode; professional type; Primary care practices across 4 centers in the UK. Callers in either intervention arm who had requested a same-day appointment would receive a call back and triage by a GP triage or a nurse with software support. | MD: Varies per arm; RN: Varies per arm; Admin/reception: Varies per arm; Dedicated staff: Yes; Access: Yes | Co-location: NR; Special training: 4-5 weeks, included commercial providers who trained staff and organization in triage practice and software; appointment request audit provided guidance in organizing the triage system; GP triage skills; and professional issues and telephone consult. | Decision support: Odyssey Patient Assess Software, Stour access system; Scope of practice described: Yes; Handoff to PCP: NR | Telephone contact; Regular clinic daytime hours; Caller ID: No
Cragg, 1997^44^; N=2,152 patients | Comparison: Local vs regional/national; Practices were randomized to have their own physicians cover out-of-hours calls vs a regional deputizing physician service within four communities. | MD: 49 practice GPs and 183 Deputizing; Dedicated staff: Yes, in practice arm; Access: NR | Co-location: NR; Special training NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; After hours; Caller ID: No
Lattimer, 1998^43^; N=14,492 calls | Comparison: Professional type; Nurse telephone triage offered to out-of-hours callers compared to a local GP out-of-hours cooperative. | Nurse (unspecified credentials): 6; Admin/reception: NR; Dedicated staff: NR; Access: NR | Co-location: Yes; Special training: 6-week training program prior to start of intervention | Decision support: Telephone advice system, interactive; Scope of practice described: no; Handoff to PCP: Yes | Telephone contact; After hours; Caller ID: No
McKinstry, 2002^42^; N=388 patients | Comparison: Mode; Telephone advice dispensed by a general practitioner that was initiated by a patient from a practice requesting a same-day appointment. Comparison group was in-person visit. | MD: NR; Dedicated staff: Yes; Access: Yes | Co-location: Yes; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: No | Telephone contact; Regular hours; Caller ID: No
Richards, 2004^40^; N=4,718 patients | Comparison: Local vs regional/national; The intervention was NHS Direct compared to in-practice nurse triage. NHS Direct is a regional nurse-led telephone triage system supported by computerized algorithms. Nurses telephoned the patient back after request for same-day appointment. | Nurse (unspecified credentials): NR; Dedicated staff: No; Access: No | Co-location: No; Special training: NR | Decision support: NHS Direct; Scope of practice described: no; Handoff to PCP: No | Telephone contact; Regular hours; Caller ID: No
Controlled Before-After
Knowles, 2016^37^; N=2,237 patients | Comparison: professional type; The study compared a new telephone triage service (NHS 111) with the existing telephone triage service (NHS Direct). NHS 111 is staffed by non-clinician call-handlers who use computerized triage software with clinician back-up to direct callers to the appropriate service or self-management advice; NHS Direct is staffed by nurses. | Nonclinical call handlers: NR; Dedicated staff: No; Access: NR | Co-located: Yes; Special training: Varied by site but generally NHS pathways training, transfer processes, communication skills, record keeping | Decision support: NHS Pathways software; Scope of practice: No; Handoff to PCP: No | Telephone contact; Regular and after hours; Caller ID: No
Munro, 2000^45^; N= 68,500 | Comparison: Local vs regional/national; NHS Direct Nurse-led telephone triage compared to local GP cooperatives. | Nurse (unspecified credentials): NR; Dedicated staff: No; Access: No | Co-location: Yes; Special training: NHS nurses were “trained to triage.” | Decision support: NHS Clinical Assessment System; Scope of practice: Yes; Handoff to PCP: Yes | Telephone contact; Regular and after hours; Caller ID: Yes
Turner, 2013^39^; N=1,802,000 calls | Comparison: Professional type; Study compared NHS 111, a 24-hour telephone triage system staffed by non-clinician call-handlers, to NHS Direct which employs nurse triage professionals. | Nurse (unspecified credentials): NR; Nonclinical call handler: NR; Dedicated staff: No; Access: No | Co-location: Yes; Special training: NR | Decision support: NHS Pathways software; Scope of practice described: Yes; Handoff to PCP: No | Telephone contact; Regular and after hours; Caller ID: No
Interrupted Time Series
Richards, 2002^41^; N=4,685 patients | Comparison: Local vs regional/national; This study randomized callers to either a small nurse triage of 6 nurses or a same-day primary care visit. Receptionists in control group were told “not to attempt any triage”. | Nurse (unspecified credentials): 6; Dedicated staff: No; Access: NR | Co-location: NR; Special training: 30 hours of minor illness management training | Decision support: protocol internally developed; Scope of practice described: no; Handoff to PCP: Yes | Telephone contact; Regular hours; Caller ID: No

a Type of professional involved in delivering the triage system.

b Dedicated triage staff are professionals whose primary job responsibility is to triage patients. This differs from staff who may have triage responsibilities in addition to their primary role.

c Decision support protocol is any tool or algorithm used to support clinical decision making or provide guidance for triage decisions.

d Scope of practice is any specific guidance about a particular staff member’s role and potential limits to their clinical discretion.

e Handoff to primary care practitioner refers to the ability for triage staff to communicate with a patient’s primary care team synchronously or asynchronously.

f Caller identification refers to the capacity to verify the identify the caller.

Abbreviations: CAS=computerized clinical assessment system; CDSS=clinical decision support system/software; CeCC=CareEnhance Call Centre software; GP=general practitioner; MD=medical doctor; NHS=National Health Service; PCP=primary care provider; RN=registered nurse

## KQ 2 Studies

Study; # Enrolled | Description of Triage System | Type/Number of Professionals^a^; Dedicated Triage Staff?^b^ | Co-located Staff?; Special Training? | Decision Support Protocol^c^; Scope of Practice Described?^d^; Handoff to PCP?^e^ | Mode of Delivery; Hours of Operation; Caller Identified?^f^
Qualitative studies
Banks, 2018^81^; N=23 | Interviews with practice staff about eConsult, an online platform, which gives patients access to advice via their GP practice website. Patients can use a symptom checker, find pharmacy advice, link to the NHS 111 service, and use an administrative service to submit an e-consultation. | MD: 10; Nurse practitioner: 1; admin/reception: 6; Practice manager: 6; Dedicated staff: No | Co-location: NR; Special training: NR | Decision support: eConsult; online; interactive; Scope of practice described: No; Handoff to PCP: Yes | Internet contact; Hours of operation: NR; Caller ID: No
Derkx, 2007^80^; N=8 | Study assessed communication skills of clinical nurse call-handlers in an out-of-hours call center in the Netherlands. | Nurse (unspecified credentials): NR; Other staff: NR; Dedicated staff: Yes | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; After hours; Caller ID: No
Eccles, 2015^62^; N=55 | A health care system in Wales changed their out-of-hours staffing system from call-handlers using protocols to a system that used call-handlers to obtain information and GPs who called patients back. Interviews with GPs and patients about perceptions. | MD: at least 40; Call Handlers: NR; Dedicated staff: Yes | Co-location: Yes; Training workshops were provided to improve triage productivity, communication skills and appropriate use of triage outcomes and telephone advice. | Decision support: protocol internally developed; Scope of practice described: Yes; Handoff to PCP: NR | Telephone contact; After hours; Caller ID: No
Edwards, 1996^67^; N=8 | Qualitative interviews with nurses from community hospitals with walk-in minor injury service that also handled phone inquiries. | Nurse (unspecified credentials): NR; Dedicated staff: Yes | Co-location: No; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Foster, 1999^63^; N=38 | Out-of-hours cooperative in South London where they handle 62% of calls by telephone alone. This particular paper documents interviews with GPs before they attended a course on how to provide advice over the phone. | MD: 38; Dedicated staff: Yes | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; After hours; Caller ID: No
Gamst-Jensen, 2017^68^; N=19 | Out-of-hours phone hotline for region in Denmark answered by nurse or MD. Interviews conducted with staff about under-triaged calls. | MD: NR; Nurse (unspecified credentials): NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: internally developed; online; expertise based; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; After hours; Caller ID: No
Greatbatch, 2005^82^; N= 60 | Qualitative study of the use of the CAS system, which mediates interactions between callers to the NHS Direct and nurses. Nurses address calls based on priority set by call-handlers. CAS then recommends a disposition. Nurse can recommend alternate dispositions if rationale are documented. | Nurse (unspecified credentials): NR Call handlers: NR; Dedicated staff: Yes | Co-location: NR; Special training: NR | Decision support: NHS Direct CAS system; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Holmström, 2007^76^; N=12 | Telephone nursing in Sweden in the early 2000s was de-centralized and not operational for 24/hrs a day. This study interviewed nurses at 1 specific call center about ethical dilemmas. | Registered Nurse: NR; Dedicated staff: Yes | Co-location: Yes; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours; Caller ID: Yes
Holmström, 2016^75^; N=10 | The national phone service in Sweden is available 24/7 but patients are instructed to call their primary health care center during regular business hours. This study looked at how elder adults perceived their experiences with local primary care nurse advice/triage lines. | Nurse (unspecified credentials): NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours; Caller ID: No
Lopriore, 2017^83^; N=196 calls | Qualitative analysis of health care triage telephone calls into HealthDirect Australia to explore health care managed over the phone. Calls were placed by patients and received by nurses using CDSS. | Registered Nurse: NR; Dedicated staff: No | Co-location: NR; Special training: NR | Decision support: computer decision support software; HealthCare Direct policy; Scope of practice described: Yes; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: Yes
O’Cathain, 2004^79^; N=24 | Description of nurse characteristics and perceptions that may lead to different triage resolution in the NHS Direct service. 24 nurses were interviewed. | Registered Nurse: 296; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: 3 different decision support softwares used by the interviewed nurses; Yes/No protocols; general guidance; and expertise based; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Pettinari, 2001^69^; N=14 | NHS Direct 24-hour nurse phone triage and helpline. Focus of study was to describe nurses’ perceptions of skills they use to manage calls without visual cues. | Nurse (unspecified credentials): NR; Dedicated staff: No | Co-location: NR; 12 weeks of training | Decision support: NHS CDSS; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Pope, 2013^72^; N=64 | Ethnographic study of computer support systems using the Normalization Process Theory. Investigators observed for 500 hours at multiple triage sites (emergency line, urgent care line, out-of-hours line). | Call handlers: 10-12 hour shifts; Supervisors: NR; Clinical support staff: NR; Dedicated staff: NR | Co-location: Yes; Emergency phone line staff received 12 days training on computer system | Decision support: Clinical Decision Support (CDS); interactive; Scope of practice described: Yes; Handoff to PCP: NR | Telephone contact; Regular and after hours; Caller ID: No
Purc-Stephenson, 2010^64^; N=16 studies | Meta-ethnography. Reviewed qualitative studies of telephone triage nurses, with aim to explore nurses’ experiences with telephone triage and advice within the primary-care sector and to understand the factors that facilitate or impede their decision making process. | Nurse (unspecified credentials): NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Richards, 2007^74^; N=27 | Three out-of-hours primary care services from different regions in England. The call is taken by a nonclinical call handler who uses a protocol to call an ambulance or provide health professional call-back. Interviews were done to explore caller experience. | MD: NR; NP: NR; Call handler: NR; Paramedic: NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: standardized protocol; Scope of practice described: No; Handoff to PCP: Yes | Telephone contact; After hours; Caller ID: No
Roberts, 2009^77^; N=35 | This study was conducted in NHS 24 (Scotland). It is “integrated as a central part of the NHS”. It is the first and only point of contact for after-hours GPs. The study’s focus was to describe stakeholder and partner views on remote and rural communities. | Nurse (unspecified credentials): NR; Dedicated staff: No | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Roing, 2015^65^; N=11 | Qualitative interviews with 6 telenurses and 5 call center managers who had been involved in malpractice claims within the Swedish Healthcare Direct, the national telenursing helpline. | Registered Nurse: 6; Call managers: 5; Dedicated staff: NR | Co-location: Yes; Special training: NR | Decision support: Decision Support Tool (DST), online; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Tariq, 2017^73^; N=9 | Qualitative interviews with nurses about the usability of the decision support system (CeCC), which provides clinical guidelines for triage nurses. | Nurse (unspecified credentials): 9; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: CeCC, online, interactive; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Timpka, 1990^70^; N=5 | Health center receptionist-nurse in a town with 30,000 people in Sweden. Qualitative analysis completed on the content of the calls between receptionist nurse & patient to describe decision-making process and communication. | Nurse (unspecified credentials): 5; Dedicated staff: No | Co-location: Yes; Special training: No | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Turnbull, 2012^78^; N=61 | Interviews to examine skills required by nonclinical call-handlers for telephone triage supported by CDSS. Call-handlers involved in triage at 999 emergency line, urgent care line, out-of-hours line. | Type of staff NR; Dedicated staff: NR | Co-location: Yes; Special training: NR | Decision support: CDSS; interactive; general guidance; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Turnbull, 2014 & 2017^71^; N=47 | 111 phone services for urgent calls that are ‘not emergent’ that are available to NHS patients 24 hrs a day. Ethnography aimed to describe work, workforce, technology, and organizational implications. | MD: NR; Registered Nurse : NR; Call advisers: 70, 30, 31, 113, 54 FT & PT depending on cite.; Other: NR; Dedicated staff: Varied by site | Co-location: Yes; Special training: 2-week training program in addition to 2 more weeks of training at the site as well as call observation and coaching. | Decision support: NHS Pathways, documented, online, interactive, Yes/No protocol; Scope of practice described: Yes; Handoff to PCP: Yes | Telephone contact; Regular hours and after hours; Caller ID: No
Wahlberg, 2018^61^; N=24 | The remote triage was completed by nurses using CDSS at Swedish Healthcare Direct. The calls were not prescreened by a call-handler. 24 interviews were completed between March and May 2015. The goal was to understand the work environment at the call center. | Nurse (unspecified credentials): 24; Dedicated staff: No | Co-location: No; Special training: NR | Decision support: Clinical; Decision Support Software (CDSS); Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Systematic reviews
Blank, 2012^66^; N=54 papers | This systematic review included studies about telephone triage. Twenty-six studies reported appropriateness of triage decisions and 26 papers reported on compliance with triage decision. Two studies reported both. | Varied by cite but included:; MD: NR; Nurse (unspecified credentials): NR; Lay operator: NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No
Bunn, 2004^21^; N=9 studies | Systematic review assessed the effects of telephone triage on safety, service usage, and patient satisfaction and compared telephone triage by different health care professionals. | Type of staff NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Carrasqueiro, 2011^36^; N=55 studies | This systematic review included studies on telephone triage to review evaluation studies and compile methodologies and metrics used as well as compare results. | Type of staff NR; Dedicated staff: NR | Co-location: NR; Special training: NR | Decision support: NR; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Hours of operation: NR; Caller ID: No
Lake, 2017^23^; N=10 systematic reviews | Review of systematic reviews focused on telephone-based triage and advice services; published since 1990; not targeting specific condition, population, medical specialty, or chronic conditions; and not related to general health education. | MD: NR; Nurse (unspecified credentials): NR; Admin/reception: NR; Health assistant: NR; Dedicated staff: other | Co-location: NR; Special training: NR | Decision support: Varied by cite; Scope of practice described: No; Handoff to PCP: NR | Telephone contact; Regular hours and after hours; Caller ID: No

a Type of professional involved in delivering the triage system.

b Dedicated triage staff are professionals whose primary job responsibility is to triage patients. This differs from staff who may have triage responsibilities in addition to their primary role.

c Decision support protocol is any tool or algorithm used to support clinical decision making or provide guidance for triage decisions.

d Scope of practice is any specific guidance about a particular staff member’s role and potential limits to their clinical discretion.

e Handoff to primary care practitioner refers to the ability for triage staff to communicate with a patient’s primary care team synchronously or asynchronously.

f Caller identification refers to the capacity to verify the identify the caller.

Abbreviations: CAS=computerized clinical assessment system; CDSS=clinical decision support software/system; CeCC=CareEnhance Call Centre software; GP-general practitioner; NHS=National Health Service; NR=not reported; PCP=primary care provider