# APPENDIX A Search Strategies

## PubMed: July 27, 2018

#1 | “Triage”[Mesh] OR triage[tiab] OR triages[tiab] OR triaged[tiab] OR triaging[tiab] OR teletriage[tiab] OR “Referral and Consultation”[Mesh:NoExp] OR “Remote Consultation”[Mesh] OR consultation[ti] OR consultation[ot] OR consultations[ti] OR consultations[ot] OR teleconsultation[tiab] OR teleconsultations[tiab] OR telenursing[tiab] OR telenurse[tiab] OR telenurses[tiab] OR “After-Hours Care”[Mesh] OR “out-of-hours”[tiab] OR “after-hours”[tiab] OR “unscheduled care”[tiab] | 95,358
#2 | “Telephone”[Mesh:NoExp] OR telephone[tiab] OR “Hotlines”[Mesh] OR hotline[tiab] OR hotlines[tiab] OR “hot line”[tiab] OR “hot lines”[tiab] OR helpline[tiab] OR helplines[tiab] OR “help line”[tiab] OR “help lines”[tiab] OR “Call Centers”[Mesh] OR “call center”[tiab] OR “call centers”[tiab] OR “call centre”[tiab] OR “call centres”[tiab] OR “communication technologies”[tiab] OR “communication technology”[tiab] OR telehealth[tiab] OR eHealth[tiab] OR mhealth[tiab] OR (“face-to-face”[tiab] AND (alternative[tiab] OR alternatives[tiab])) OR (“communication”[tiab] AND (alternative[tiab] OR alternatives[tiab])) OR (“in-person”[tiab] AND (alternative[tiab] OR alternatives[tiab])) OR (“inperson”[tiab] AND (alternative[tiab] OR alternatives[tiab])) OR virtual[ti] OR ((“After-Hours Care”[Mesh]) AND “Primary Health Care”[Mesh]) OR ((“after hours”[ti] OR “out of hours”[ti]) AND (“primary medical care”[ti] OR “primary care”[ti] OR “general medicine”[ti])) | 91,636
#3 | #1 AND #2 | 5,274
#4 | #3 AND English[lang] | 4,970
#5 | #4 AND (“1990/01/01”[Date - Publication] : “3000”[Date - Publication]) | 4,711
#6 | #5 NOT (animals[mh] NOT humans[mh]) | 4,707
#7 | #6 NOT ((“Adolescent”[Mesh] OR “Child”[Mesh] OR “Infant”[Mesh]) NOT “Adult”[Mesh]) | 4,311
#8 (KQ1) | #7 AND ((“randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR drug therapy[sh] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR non-random[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR (controlled[tiab] AND (trial[tiab] OR study[tiab])) OR “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR pre-test[tiab] OR (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab])) NOT (Editorial[ptyp] OR Letter[ptyp] OR Comment[ptyp])) | 2,289
#9 (KQ2) | #7 NOT (Editorial[ptyp] OR Letter[ptyp] OR Comment[ptyp]) | 4,108

## Embase: July 27, 2018

#1 | triage:ti,ab OR triages:ti,ab OR triaged:ti,ab OR triaging:ti,ab OR teletriage:ti,ab OR consultation:ti OR consultation:kw OR consultations:ti OR consultations:kw OR ‘teleconsultation’/exp OR teleconsultation:ti,ab OR teleconsultations:ti,ab OR telenursing:ti,ab OR telenurse:ti,ab OR telenurses:ti,ab OR ‘out-of-hours care’/exp OR ‘out-of-hours’:ti,ab OR ‘after-hours’:ti,ab OR ‘unscheduled care’:ti,ab | 56,847
#2 | ‘telephone’/exp OR telephone:ti,ab OR ‘hotline’/exp OR hotline:ti,ab OR hotlines:ti,ab OR ‘hot line’:ti,ab OR ‘hot lines’:ti,ab OR helpline:ti,ab OR helplines:ti,ab OR ‘help line’:ti,ab OR ‘help lines’:ti,ab OR ‘call center’/exp OR ‘call center’:ti,ab OR ‘call centers’:ti,ab OR ‘call centre’:ti,ab OR ‘call centres’:ti,ab OR ‘communication technologies’:ti,ab OR ‘communication technology’:ti,ab OR telehealth:ti,ab OR ehealth:ti,ab OR mhealth:ti,ab OR (((‘face-to-face’ OR ‘communication’ OR ‘in-person’ OR ‘inperson’) NEAR/4 (alternative OR alternatives)):ti,ab) OR (((‘after hours’ OR ‘out of hours’) NEAR/3 (‘primary’ OR ‘general’)):ti,ab) | 92,056
#3 | #1 AND #2 | 6,891
#4 | #3 AND [humans]/lim AND [english]/lim AND [1990-2018]/py | 5,961
#5 | #4 NOT (([embryo]/lim OR [fetus]/lim OR [newborn]/lim OR [infant]/lim OR [child]/lim OR [preschool]/lim OR [school]/lim) NOT ([young adult]/lim OR [adult]/lim OR [middle aged]/lim OR [aged]/lim OR [very elderly]/lim)) | 5,442
#6 (KQ1) | #5 AND (‘randomized controlled trial’/exp OR ‘crossover procedure’/exp OR ‘double blind procedure’/exp OR ‘single blind procedure’/exp OR random*:ti,ab OR factorial*:ti,ab OR crossover*:ti,ab OR ((cross NEAR/1 over*):ti,ab) OR placebo*:ti,ab OR ((doubl* NEAR/1 blind*):ti,ab) OR ((singl* NEAR/1 blind*):ti,ab) OR assign*:ti,ab OR allocat*:ti,ab OR volunteer*:ti,ab OR ‘clinical study’/exp OR ‘clinical trial’:ti,ab OR ‘clinical trials’:ti,ab OR ‘controlled study’/exp OR ‘evaluation’/exp OR ‘evaluation study’:ti,ab OR ‘evaluation studies’:ti,ab OR ‘intervention study’:ti,ab OR ‘intervention studies’:ti,ab OR ‘case control’:ti,ab OR ‘cohort analysis’/exp OR cohort:ti,ab OR longitudinal*:ti,ab OR prospective:ti,ab OR prospectively:ti,ab OR retrospective:ti,ab OR ‘follow up’/exp OR ‘follow up’:ti,ab OR ‘comparative effectiveness’/exp OR ‘comparative study’/exp OR ‘comparative study’:ti,ab OR ‘comparative studies’:ti,ab OR ‘evidence based medicine’/exp) NOT (‘case report’/exp OR ‘a case report’:ti OR ‘: case report’:ti OR ‘case study’/exp OR ‘editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [editorial]/lim OR [letter]/lim OR [note]/lim OR [conference abstract]/lim) | 2,662
#7 (KQ2) | #5 NOT (‘editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [editorial]/lim OR [letter]/lim OR [note]/lim OR [conference abstract]/lim) | 3,750

## CINAHL: July 27, 2018

S1 | (MH “Triage”) OR (MH “Remote Consultation”) OR TI (triage OR triages OR triaged OR triaging OR teletriage OR consultation OR consultations OR teleconsultation OR teleconsultations OR telenursing OR telenurse OR telenurses OR “out-of-hours" OR “after-hours" OR “unscheduled care”) OR AB (triage OR triages OR triaged OR triaging OR teletriage OR consultation OR consultations OR teleconsultation OR teleconsultations OR telenursing OR telenurse OR telenurses OR “out-of-hours” OR “after-hours” OR “unscheduled care”) | 40,009
S2 | (MH “Telehealth+”) OR (MH “Remote Access to Information”) OR TI (telephone OR telephones OR hotline OR hotlines OR “hot line” OR “hot lines” OR helpline OR helplines OR “help line” OR “help lines” OR “call center” OR “call centers” OR “communication technologies” OR “communication technology” OR telehealth OR eHealth OR mhealth) OR AB (telephone OR telephones OR hotline OR hotlines OR “hot line” OR “hot lines” OR helpline OR helplines OR “help line” OR “help lines” OR “call center” OR “call centers” OR “communication technologies” OR “communication technology” OR telehealth OR eHealth OR mhealth) | 44,713
S3 | S1 AND S2; Limiters - English Language; Peer Reviewed; Published Date: 19900101-20180731; Exclude MEDLINE records | 961