# REFERENCES

1 Chandra RA, Keane FK, Voncken FEM, Thomas CR, Jr. Contemporary radiotherapy: present and future. Lancet. Jul 10 2021;398(10295):171–184. doi:10.1016/s0140-6736(21)00233-6 34166607
2 Miller KD, Nogueira L, Devasia T, . Cancer treatment and survivorship statistics, 2022. CA Cancer J Clin. Sep 2022;72(5):409–436. doi:10.3322/caac.21731 35736631
3 Saini A KM, Bhatt S, Saini V, Malik A. Cancer causes and treatments. International Journal of Pharmaceutical Sciences and Research. 2020;11(7):3121–34.
4 Baskar R, Lee KA, Yeo R, Yeoh KW. Cancer and radiation therapy: current advances and future directions. Int J Med Sci. 2012;9(3):193–9. doi:10.7150/ijms.3635 22408567
5 Wang JS, Wang HJ, Qian HL. Biological effects of radiation on cancer cells. Mil Med Res. Jun 30 2018;5(1):20. doi:10.1186/s40779-018-0167-4 29958545
6 Torres Royo L, Antelo Redondo G, Árquez Pianetta M, Arenas Prat M. Low-Dose radiation therapy for benign pathologies. Rep Pract Oncol Radiother. Mar–Apr 2020;25(2):250–254. doi:10.1016/j.rpor.2020.02.004 32140081
7 Hu ZH, Chen W, Sun JN, . Radiotherapy for the prophylaxis of heterotopic ossification after total hip arthroplasty: A systematic review and meta-analysis of randomized controlled trails. Med Dosim. Spring 2021;46(1):65–73. doi:10.1016/j.meddos.2020.07.010 32928622
8 Thompson AM, Seivright J, Atluri S, . Radiotherapy for Hidradenitis Suppurativa: A Systematic Review. Dermatology. 2021;237(3):357–364. doi:10.1159/000514027 33535201
9 Shin JY, Lee JW, Roh SG, Lee NH, Yang KM. A Comparison of the Effectiveness of Triamcinolone and Radiation Therapy for Ear Keloids after Surgical Excision: A Systematic Review and Meta-Analysis. Plast Reconstr Surg. Jun 2016;137(6):1718–1725. doi:10.1097/prs.0000000000002165 27219228
10 Eng TY, Abugideiri M, Chen TW, . Radiation Therapy for Benign Disease: Keloids, Macular Degeneration, Orbital Pseudotumor, Pterygium, Peyronie Disease, Trigeminal Neuralgia. Hematol Oncol Clin North Am. Feb 2020;34(1):229–251. doi:10.1016/j.hoc.2019.09.006 31739946
11 Dove APH, Cmelak A, Darrow K, . The Use of Low-Dose Radiation Therapy in Osteoarthritis: A Review. Int J Radiat Oncol Biol Phys. Oct 1 2022;114(2):203–220. doi:10.1016/j.ijrobp.2022.04.029 35504501
12 Canyilmaz E, Canyilmaz F, Aynaci O, . Prospective Randomized Comparison of the Effectiveness of Radiation Therapy and Local Steroid Injection for the Treatment of Plantar Fasciitis. Int J Radiat Oncol Biol Phys. Jul 1 2015;92(3):659–66. doi:10.1016/j.ijrobp.2015.02.009 25936814
13 Nardone V, D’Ippolito E, Grassi R, . Non-Oncological Radiotherapy: A Review of Modern Approaches. J Pers Med. Oct 9 2022;12(10)doi:10.3390/jpm12101677
14 Radiotherapy for non-malignant disorders. Springer Berlin Heidelberg; 2008.
15 Seegenschmiedt MH, Micke O, Muecke R. Radiotherapy for non-malignant disorders: state of the art and update of the evidence-based practice guidelines. Br J Radiol. Jul 2015;88(1051):20150080. doi:10.1259/bjr.20150080 25955230
16 Seegenschmiedt MH, Micke O, Niewald M, . DEGRO guidelines for the radiotherapy of non-malignant disorders : part III: hyperproliferative disorders. Strahlenther Onkol. Jul 2015;191(7):541–8. doi:10.1007/s00066-015-0818-2 25753848
17 Ott OJ, Niewald M, Weitmann HD, . DEGRO guidelines for the radiotherapy of non-malignant disorders. Part II: Painful degenerative skeletal disorders. Strahlenther Onkol. Jan 2015;191(1):1–6. doi:10.1007/s00066-014-0757-3
18 Pendlebury GA, Oro P, Ludlow K, Merideth D, Haynes W, Shrivastava V. Relevant Dermatoses Among U.S. Military Service Members: An Operational Review of Management Strategies and Telemedicine Utilization. Cureus. Jan 2023;15(1):e33274. doi:10.7759/cureus.33274 36741595
19 Grimm PD, Mauntel TC, Potter BK. Combat and Noncombat Musculoskeletal Injuries in the US Military. Sports Med Arthrosc Rev. Sep 2019;27(3):84–91. doi:10.1097/jsa.0000000000000246 31361716
20 Singh R, Kelly KA, Senthilnathan A, Feldman SR, Pichardo RO. Stigmatization, a social perception which may have a debilitating impact on hidradenitis suppurativa patients: an observational study. Arch Dermatol Res. May 2023;315(4):1049–1052. doi:10.1007/s00403-022-02412-5 36315267
21 Macaulay D, Ivanova J, Birnbaum H, Sorg R, Skodny P. Direct and indirect costs associated with Dupuytren’s contracture. J Med Econ. 2012;15(4):664–71. doi:10.3111/13696998.2012.670678 22369346
22 The Burden of Musculoskeletal Diseases in the United States (BMUS). United States Bone and Joint Initiative. 2023. http://www.boneandjointburden.org
23 Brown KV, Dharm-Datta S, Potter BK, . Comparison of development of heterotopic ossification in injured US and UK Armed Services personnel with combat-related amputations: preliminary findings and hypotheses regarding causality. J Trauma. Jul 2010;69 Suppl 1:S116–22. doi:10.1097/TA.0b013e3181e44cc7 20622605
24 Hoyt BW, Pavey GJ, Potter BK, Forsberg JA. Heterotopic ossification and lessons learned from fifteen years at war: A review of therapy, novel research, and future directions for military and civilian orthopaedic trauma. Bone. Apr 2018;109:3–11. doi:10.1016/j.bone.2018.02.009 29462673
25 Porter KS, Harrington CJ, Babikian A, . Heterotopic Ossification Formation in Military Beneficiaries Following Hip- and Pelvic-Level Amputations. Mil Med. May 11 2023;doi:10.1093/milmed/usad129
26 Potter BK, Burns TC, Lacap AP, Granville RR, Gajewski DA. Heterotopic ossification following traumatic and combat-related amputations. Prevalence, risk factors, and preliminary results of excision. J Bone Joint Surg Am. Mar 2007;89(3):476–86. doi:10.2106/jbjs.F.00412 17332095
27 Forsberg JA, Pepek JM, Wagner S, . Heterotopic ossification in high-energy wartime extremity injuries: prevalence and risk factors. J Bone Joint Surg Am. May 2009;91(5):1084–91. doi:10.2106/jbjs.H.00792 19411456
28 Dominick KL, Golightly YM, Jackson GL. Arthritis prevalence and symptoms among US non-veterans, veterans, and veterans receiving Department of Veterans Affairs Healthcare. J Rheumatol. Feb 2006;33(2):348–54.16465668
29 Owens BD, Wolf JM, Seelig AD, . Risk Factors for Lower Extremity Tendinopathies in Military Personnel. Orthop J Sports Med. Jan–Jun 2013;1(1):2325967113492707. doi:10.1177/2325967113492707 26535232
30 Scher DL, Belmont PJ, Jr., Bear R, Mountcastle SB, Orr JD, Owens BD. The incidence of plantar fasciitis in the United States military. J Bone Joint Surg Am. Dec 2009;91(12):2867–72. doi:10.2106/jbjs.I.00257 19952249
31 Wallace BC, Small K, Brodley CE, Lau J, Trikalinos TA. Deploying an interactive machine learning system in an evidence-based practice center: abstrackr. presented at: Proceedings of the 2nd ACM SIGHIT International Health Informatics Symposium; 2012; Miami, Florida, USA. 10.1145/2110363.2110464
32 Treadwell JR, Singh S, Talati R, McPheeters ML, Reston JT. AHRQ Methods for Effective Health Care. A Framework for “Best Evidence” Approaches in Systematic Reviews. Agency for Healthcare Research and Quality (US); 2011.
33 Sterne JA, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. Bmj. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
34 Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. Bmj. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
35 Guyatt GH, Oxman AD, Vist GE, . GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. Apr 26 2008;336(7650):924–6. doi:10.1136/bmj.39489.470347.AD 18436948
36 Bremen-Kühne RV, Stock D, Franke C. Indomethacin-short-term-therapy vs. single-low-dose-radiatio for prophylaxis of periarticular ossifications (PAO) following total hip arthroplasty. Article. Zeitschrift fur Orthopadie und Ihre Grenzgebiete. 1997;135(5):422–429. doi:10.1055/s-2008-1039411 9446435
37 Burd TA, Hughes MS, Anglen JO. Heterotopic ossification prophylaxis with indomethacin increases the risk of long-bone nonunion. J Bone Joint Surg Br. Jul 2003;85(5):700–5.12892193
38 Hamid N, Ashraf N, Bosse MJ, . Radiation therapy for heterotopic ossification prophylaxis acutely after elbow trauma: a prospective randomized study. J Bone Joint Surg Am. Sep 1 2010;92(11):2032–8. doi:10.2106/jbjs.I.01435 20810853
39 Ince A, Sauer U, Wollmerstedt N, Hendrich C. No migration of acetabular cups after prophylaxis for heterotopic ossification. Clin Orthop Relat Res. Aug 2007;461:125–9. doi:10.1097/BLO.0b013e31805c0d82 17415004
40 Kienapfel H, Koller M, Wüst A, . Prevention of heterotopic bone formation after total hip arthroplasty: a prospective randomised study comparing postoperative radiation therapy with indomethacin medication. Arch Orthop Trauma Surg. 1999;119(5–6):296–302. doi:10.1007/s004020050414 10447627
41 Kölbl O, Knelles D, Barthel T, Kraus U, Flentje M, Eulert J. Randomized trial comparing early postoperative irradiation vs. the use of nonsteroidal antiinflammatory drugs for prevention of heterotopic ossification following prosthetic total hip replacement. Int J Radiat Oncol Biol Phys. Dec 1 1997;39(5):961–6. doi:10.1016/s0360-3016(97)00496-3 9392532
42 Kölbl O, Knelles D, Barthel T, Raunecker F, Flentje M, Eulert J. Preoperative irradiation versus the use of nonsteroidal anti-inflammatory drugs for prevention of heterotopic ossification following total hip replacement: the results of a randomized trial. Int J Radiat Oncol Biol Phys. Sep 1 1998;42(2):397–401. doi:10.1016/s0360-3016(98)00204-1 9788422
43 Van Leeuwen WM, Deckers P, De Lange WJ. Preoperative irradiation for prophylaxis of ectopic ossification after hip arthroplasty. Article. Acta Orthopaedica Scandinavica. 1998;69(2):116–118. doi:10.3109/17453679809117609 9602765
44 Moore KD, Goss K, Anglen JO. Indomethacin versus radiation therapy for prophylaxis against heterotopic ossification in acetabular fractures. Article. Journal of Bone and Joint Surgery - Series B. 1998;80(2):259–263. doi:10.1302/0301-620X.80B2.8157
45 Sell S, Willms R, Jany R, . The suppression of heterotopic ossifications: Radiation versus NSAID therapy - A prospective study. Article. Journal of Arthroplasty. 1998;13(8):854–859. doi:10.1016/S0883-5403(98)90189-9 9880175
46 Akinbiyi T, Kozak GM, Davis HD, . Contemporary treatment of keloids: A 10-year institutional experience with medical management, surgical excision, and radiation therapy. Am J Surg. Apr 2021;221(4):689–696. doi:10.1016/j.amjsurg.2020.07.035 32878694
47 Qiao XF, Li X. [Comparative study of surgical treatment combined with various methods for treatment of ear scar]. Lin Chung Er Bi Yan Hou Tou Jing Wai Ke Za Zhi. Sep 5 2017;31(17):1341–1343. doi:10.13201/j.issn.1001-1781.2017.17.011
48 Aluko-Olokun B, Olaitan AA, Ladeinde AL, Oginni FO. The facial keloid: A comparison of treatment outcome between intralesional steroid injection and excision combined with radiotherapy. Article. European Journal of Plastic Surgery. 2014;37(7):361–366. doi:10.1007/s00238-014-0957-1
49 Khalid FA, Farooq UK, Saleem M, . The efficacy of excision followed by intralesional 5-fluorouracil and triamcinolone acetonide versus excision followed by radiotherapy in the treatment of ear keloids: A randomized control trial. Burns. Sep 2018;44(6):1489–1495. doi:10.1016/j.burns.2018.02.017 29534885
50 Li Y, Zhang D, Hang B, Wang H. The Efficacy of Combination Therapy Involving Excision Followed by Intralesional 5-Fluorouracil and Betamethasone, and Radiotherapy in the Treatment of Keloids: A Randomized Controlled Trial. Clin Cosmet Investig Dermatol. 2022;15:2845–2854. doi:10.2147/ccid.S388717
51 Sclafani AP, Gordon L, Chadha M, Romo T, 3rd. Prevention of earlobe keloid recurrence with postoperative corticosteroid injections versus radiation therapy: a randomized, prospective study and review of the literature. Dermatol Surg. Jun 1996;22(6):569–74. doi:10.1111/j.1524-4725.1996.tb00376.x 8646474
52 Gogna P, Gaba S, Mukhopadhyay R, Gupta R, Rohilla R, Yadav L. Plantar fasciitis: A randomized comparative study of platelet rich plasma and low dose radiation in sportspersons. Foot (Edinb). Aug 2016;28:16–19. doi:10.1016/j.foot.2016.08.002 27521483
53 Aynaci Ö, Zengin AY, Serdar L, . Comparison of effectiveness of radiation therapy, local steroid injection, and extracorporeal shock wave therapy in patients with plantar fasciitis: A multicenter study. Article. Turk Onkoloji Dergisi. 2021;36(3):329–337. doi:10.5505/tjo.2021.2731
54 Rudat V, Tontcheva N, Kutz G, Orovwighose TO, Gebhardt E. Long-term effect and prognostic factors of a low-dose radiotherapy of painful plantar calcaneal spurs : A retrospective unicenter study. Strahlenther Onkol. Oct 2021;197(10):876–884. doi:10.1007/s00066-020-01741-6 33502569
55 Hermann RM, Meyer A, Becker A, . Effect of field size and length of plantar spur on treatment outcome in radiation therapy of plantar fasciitis: the bigger the better? Int J Radiat Oncol Biol Phys. Dec 1 2013;87(5):1122–8. doi:10.1016/j.ijrobp.2013.08.042 24120823
56 Viani GA, Fonseca EC, De Fendi LI, Rocha EM. Conjunctival autograft alone or combined with adjuvant beta-radiation? A randomized clinical trial. Int J Radiat Oncol Biol Phys. Mar 1 2012;82(3):e507–11. doi:10.1016/j.ijrobp.2011.06.1988 22284040
57 Frucht-Pery J, Ilsar M. The use of low-dose mitomycin C for prevention of recurrent pterygium. Ophthalmology. Apr 1994;101(4):759–62. doi:10.1016/s0161-6420(94)31269-3 8152772
58 Bekibele CO, Baiyeroju AM, Ajayi BGK. 5-flourouracil vs. beta-irradiation in the prevention of pterygium recurrence. Article. International Journal of Clinical Practice. 2004;58(10):920–923. doi:10.1111/j.1742-1241.2004.00007.x 15587769
59 Simşek T, Günalp I, Atilla H. Comparative efficacy of beta-irradiation and mitomycin-C in primary and recurrent pterygium. Eur J Ophthalmol. Apr–Jun 2001;11(2):126–32. doi:10.1177/112067210101100204 11456012
60 Isohashi F, Inoue T, Xing S, Eren CB, Ozeki S, Inoue T. Postoperative irradiation for pterygium: retrospective analysis of 1,253 patients from the Osaka University Hospital. Strahlenther Onkol. Aug 2006;182(8):437–42. doi:10.1007/s00066-006-1484-1 16896589
61 Willner J, Flentje M, Lieb W. Soft X-ray therapy of recurrent pterygium--an alternative to 90Sr eye applicators. Strahlenther Onkol. Aug 2001;177(8):404–9. doi:10.1007/pl00002422 11544903
62 Minten MJ, Mahler E, den Broeder AA, Leer JW, van den Ende CH. The efficacy and safety of low-dose radiotherapy on pain and functioning in patients with osteoarthritis: a systematic review. Rheumatol Int. Jan 2016;36(1):133–42. doi:10.1007/s00296-015-3337-7 26747050
63 Mahler EAM, Minten MJ, Leseman-Hoogenboom MM, . Effectiveness of low-dose radiation therapy on symptoms in patients with knee osteoarthritis: a randomised, double-blinded, sham-controlled trial. Ann Rheum Dis. Jan 2019;78(1):83–90. doi:10.1136/annrheumdis-2018-214104 30366945
64 Minten MJM, Leseman-Hoogenboom MM, Kloppenburg M, . Lack of beneficial effects of low-dose radiation therapy on hand osteoarthritis symptoms and inflammation: a randomised, blinded, sham-controlled trial. Osteoarthritis Cartilage. Oct 2018;26(10):1283–1290. doi:10.1016/j.joca.2018.06.010 30231990
65 Rühle A, Tkotsch E, Mravlag R, . Low-dose radiotherapy for painful osteoarthritis of the elderly: A multicenter analysis of 970 patients with 1185 treated sites. Strahlenther Onkol. Oct 2021;197(10):895–902. doi:10.1007/s00066-021-01816-y 34342662
66 Weissmann T, Rückert M, Zhou JG, . Low-Dose Radiotherapy Leads to a Systemic Anti-Inflammatory Shift in the Pre-Clinical K/BxN Serum Transfer Model and Reduces Osteoarthritic Pain in Patients. Front Immunol. 2021;12:777792. doi:10.3389/fimmu.2021.777792 35046940
67 Niewald M, Müller LN, Hautmann MG, . ArthroRad trial: multicentric prospective and randomized single-blinded trial on the effect of low-dose radiotherapy for painful osteoarthritis depending on the dose-results after 3 months’ follow-up. Strahlenther Onkol. Apr 2022;198(4):370–377. doi:10.1007/s00066-021-01866-2 34724085
68 Incrocci L, Hop WC, Slob AK. Current sexual functioning in 106 patients with Peyronie’s disease treated with radiotherapy 9 years earlier. Urology. Dec 20 2000;56(6):1030–4. doi:10.1016/s0090-4295(00)00805-0 11113753
69 Niewald M, Wenzlawowicz KV, Fleckenstein J, Wisser L, Derouet H, Rübe C. Results of radiotherapy for Peyronie’s disease. Int J Radiat Oncol Biol Phys. Jan 1 2006;64(1):258–62. doi:10.1016/j.ijrobp.2005.06.009 16169684
70 Pietsch G, Anzeneder T, Bruckbauer H, . Superficial radiation therapy in peyronie’s disease: An effective and well-tolerated therapy. Adv Radiat Oncol. Oct–Dec 2018;3(4):548–551. doi:10.1016/j.adro.2018.07.009 30370354
71 Pambor C, Gademann G. Indurallo Penis Plastica. Article. Strahlentherapie und Onkologie. 2003;179(11):787–790. doi:10.1007/s00066-003-1022-3 14605750
72 Meineke V, Uebler C, Köhn FM, . [Radiotherapy in benign diseases: Morbus Peyronie]. Strahlenther Onkol. Mar 2003;179(3):181–6. Strahlentherapie benigner Erkrankungen: Morbus Peyronie. doi:10.1007/s00066-003-0984-5 12627261
73 Betz N, Ott OJ, Adamietz B, Sauer R, Fietkau R, Keilholz L. Radiotherapy in early-stage Dupuytren’s contracture. Long-term results after 13 years. Strahlenther Onkol. Feb 2010;186(2):82–90. doi:10.1007/s00066-010-2063-z 20127225
74 Keilholz L, Seegenschmiedt MH, Sauer R. Radiotherapy for prevention of disease progression in early-stage Dupuytren’s contracture: initial and long-term results. Int J Radiat Oncol Biol Phys. Nov 1 1996;36(4):891–7. doi:10.1016/s0360-3016(96)00421-x 8960518
75 Latusek T, Miszczyk L, Gierlach G, Zajac P. An effectiveness evaluation of the palmar fascia irradiation of patients suffering from Dupuytren’s disease. Article. Nowotwory. 2017;67(3):162–167. doi:10.5603/NJO.2017.0027
76 Zirbs M, Anzeneder T, Bruckbauer H, . Radiotherapy with soft X-rays in Dupuytren’s disease - successful, well-tolerated and satisfying. J Eur Acad Dermatol Venereol. May 2015;29(5):904–11. doi:10.1111/jdv.12711 25201324
77 Adamietz B, Keilholz L, Grünert J, Sauer R. Radiotherapy in early stage Dupuytren’s contracture. Article. Strahlentherapie und Onkologie. 2001;177(11):604–610. doi:10.1007/pl00002371 11757183
78 de Haan A, van Nes JGH, Kolff MW, . Radiotherapy for Ledderhose disease: Results of the LedRad-study, a prospective multicentre randomised double-blind phase 3 trial. Radiother Oncol. Aug 2023;185:109718. doi:10.1016/j.radonc.2023.109718 37211283
79 de Haan A, van Nes JGH, Werker PMN, Langendijk JA, Steenbakkers RJHM. Radiotherapy for patients with Ledderhose disease: Long-term effects, side effects and patient-rated outcome. Article. Radiotherapy and Oncology. 2022;168:83–88. doi:10.1016/j.radonc.2022.01.031 35101465
80 Heyd R, Dorn AP, Herkströter M, Rödel C, Müller-Schimpfle M, Fraunholz I. Radiation therapy for early stages of morbus Ledderhose. Strahlenther Onkol. Jan 2010;186(1):24–29. doi:10.1007/s00066-009-2049-x 20082184
81 Seegenschmiedt MH, Attassi M. [Radiation therapy for Morbus Ledderhose -- indication and clinical results]. Strahlenther Onkol. Dec 2003;179(12):847–53. Strahlentherapie beim Morbus Ledderhose-Indikation und klinische Ergebnisse. doi:10.1007/s00066-003-0994-3 14652674
82 Fröhlich D, Baaske D, Glatzel M. [Radiotherapy of hidradenitis suppurativa--still valid today?]. Strahlenther Onkol. Jun 2000;176(6):286–9. Strahlentherapie der Hidradenitis axillaris--heute noch aktuell?10897256
83 Shah DJ, Sachs Rk Fau - Wilson DJ, Wilson DJ. Radiation-induced cancer: a modern view. (1748-880X (Electronic))
84 Eng TY, Boersma MK, Fuller CD, . The role of radiation therapy in benign diseases. Hematol Oncol Clin North Am. Apr 2006;20(2):523–57. doi:10.1016/j.hoc.2006.01.023 16730305
85 Dawson GA, Cheuk AV, Lutz S, . The Availability of Advanced Radiation Oncology Technology within the Veterans Health Administration Radiation Oncology Centers. (1945-337X (Electronic))
86 Shekelle P, Maggard-Gibbons M, Blegen M, . VA versus Non-VA Quality of Care: A Systematic Review. Washington (DC): Department of Veterans Affairs (US); April 2023.
87 Park J, Puckett LL, Katsoulakis E, . Veterans Affairs Radiation Oncology Quality Surveillance Program and American Society for Radiation Oncology Quality Measures Initiative. (1879-8519 (Electronic))
88 Puckett LL, Kodali D, Solanki AA, . Consensus Quality Measures and Dose Constraints for Breast Cancer From the Veterans Affairs Radiation Oncology Quality Surveillance Program and American Society for Radiation Oncology Expert Panel. Pract Radiat Oncol. May–Jun 2023;13(3):217–230. doi:10.1016/j.prro.2022.08.016 36115498
89 Park J, Venkatesulu BP, Kujundzic K, . Consensus Quality Measures and Dose Constraints for Rectal Cancer From the Veterans Affairs Radiation Oncology Quality Surveillance Program and American Society for Radiation Oncology (ASTRO) Expert Panel. Pract Radiat Oncol. Sep–Oct 2022;12(5):424–436. doi:10.1016/j.prro.2022.05.005 35907764
90 Solanki AA, Puckett LL, Kujundzic K, . Consensus Quality Measures and Dose Constraints for Prostate Cancer From the Veterans Affairs Radiation Oncology Quality Surveillance Program and American Society for Radiation Oncology Expert Panel. Pract Radiat Oncol. Mar–Apr 2023;13(2):e149–e165. doi:10.1016/j.prro.2022.08.018 36522277
91 Katsoulakis E, Kudner R, Chapman C, . Consensus Quality Measures and Dose Constraints for Head and Neck Cancer with an emphasis on Oropharyngeal and Laryngeal Cancer from the Veterans Affairs Radiation Oncology Quality Surveillance Program and American Society for Radiation Oncology Expert Panel. (1879-8519 (Electronic))