# ACKNOWLEDGMENTS

The authors are grateful to Gaelen Adam, MLIS for literature searching and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Albert Chen, MD, PhD
  Chief, Radiotherapy
  Michael E. DeBakey VA Medical Center
- Steve Lee, MD, PhD
  Chief, Radiation Oncology
  Desert Pacific Healthcare Network (VISN 22)

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Tony Y. Eng, MD
  Professor
  Department of Radiation Oncology, Emory University School of Medicine
- Aaron H. Wolfson, MD, FACR
  Professor
  Department of Radiation Oncology, University of Miami