# DISCUSSION

Overall, we identified 48 studies (21 RCTs, 5 NRCS, 21 single group studies, and 1 systematic review) across 9 diseases of interest. All the studies reported data on disease related symptoms. Studies less frequently reported data on side effects or patient satisfaction, experience, or quality of life. Only 5 studies were conducted in the US, and none were conducted in the VA.

Heterotopic Ossification

- There was a clinical reduction in the occurrence of heterotopic ossification after RT and surgery without NSAIDs (low confidence). The difference was not statistically significant.
- There was no significant difference in function between RT and surgery with or without NSAIDs (low confidence).
- Studies provided insufficient evidence (no conclusion) for radiologic failure, side effects, and patient satisfaction, experience of care, or quality of life.

Keloids

- There was no significant difference in pain after RT (low confidence).
- Studies provided insufficient evidence (no conclusions) for keloid recurrence, cosmetic outcomes, skin conditions, or side effects and complications.
- Studies did not report patient satisfaction, experience, or quality of life.

Plantar Fasciitis

- Function may improve after RT compared to alternative treatments (low confidence).
- There was no significant difference in plantar fasciitis thickness, a composite measure of pain and function, and side effects (low confidence).
- Studies provided insufficient evidence (no conclusion) for pain or use of secondary treatment. Studies did not report patient satisfaction or quality of life.

Pterygium (Brachytherapy)

- Studies provided insufficient evidence (no conclusion) for the recurrence of pterygium, symptom improvement, cosmetic results, or side effects.
- Studies did not report patient satisfaction, experience, or quality of life.

Pterygium (Non-Brachytherapy; Certainty of Evidence Not Assessed)

- There was a reduction in recurrence after RT.
- Studies did not report side effects, patient satisfaction, experience, or quality of life.

Osteoarthritis (Certainty of Evidence Not Assessed)

- There was no significant change in pain, function, stiffness, patient global assessment, composite measure of pain and function, and mental or physical health in 2 RCTs. Single group studies found significant improvements in disease-related outcomes.
- Side effects (fatigue, local reactions, skin reactions, and nail reactions) were comparable between RT and sham RT.
- Short Form Health Survey scores increased after RT in single group studies, but not RCTs. Studies did not report patient satisfaction or experience.

Peyronie’s Disease (Certainty of Evidence Not Assessed)

- Disease-related symptoms improved after RT including pain, deviation/curvature, erectile disfunction, and number, size, and quality of foci.
- Side effects ranged from 0% (long-term side effect) to 39% (erythema).
- Some patients were satisfied with their sex life after RT. Studies did not report patient experience or quality of life.

Dupuytren’s Contracture (Certainty of Evidence Not Assessed)

- Disease stage, nodules, and symptoms either stabilized or regressed in most patients after RT.
- Skin-related complications were the most commonly reported side effect.
- Most patients were satisfied with RT. Studies did not report on quality of life.

Ledderhose Disease (Certainty of Evidence Not Assessed)

- Pain, walking speed, step rate, and quality of life improved after RT compared to sham RT.
- Lesions and symptoms stabilized and nodes and strands decreased after RT.
- Side effects ranged from 3% to 33% and included erythema, dryness, soft tissue fibrosis, and redness of the skin.
- Most patients were satisfied (overall or specific to function) with RT.

Hidradenitis Suppurativa (Certainty of Evidence Not Assessed)

- Clinical symptoms either resolved or improved after RT.
- Side effects and patient satisfaction, experience, or quality of life were not reported.

## SUMMARY

Inflammatory, degenerative, and benign proliferative musculoskeletal conditions, such as heterotopic ossification, keloids, plantar fasciitis, and osteoarthritis can lead to pain, physical limitations, depression, anxiety, financial strain, and lower quality of life.^6–10^ RT, typically employed to treat cancer, has also been used to treat these benign inflammatory and degenerative musculoskeletal conditions. Clinically, RT is hypothesized to reduce cell proliferation, which is the main pathology underlying many of these benign conditions.^43,62^ Although in Germany an estimated 10-30% of RT is applied to treat benign diseases, there are surprisingly few comparative studies on the effectiveness of RT for the 9 diseases prioritized in this review.^13–16^

The effect of RT on outcomes is mixed among the 4 diseases for which were able to evaluate certainty of evidence. RT reduced the occurrence of heterotopic ossification, and improved function for people with plantar fasciitis. The studies on heterotopic ossification at follow-up reported point estimates that strongly favored RT and were clinically meaningful, but the pooled effect estimate was accompanied by a very wide confidence interval and was not statistically significant. RT was not uniformly associated with clinical benefits within a disease. For example, there were clinically meaningful improvements in function after RT for patients with plantar fasciitis, but there was no significant difference in thickness, a composite measure that included function, and insufficient evidence for pain. Importantly, most studies found minimal evidence of adverse events, indicating that RT may be a safe treatment. However, these studies did not consistently report adverse events and at times it was unclear whether an adverse event was due to RT, co-occurring intervention (eg, surgery), or a natural feature of the lesion. While RT shows promise as a treatment modality for some of the prioritized diseases, findings are based on mostly small studies with heterogenous comparison groups, follow-up duration, and RT dosing.

Single group studies predominantly informed the synthesis of the diseases for which we were unable to evaluate certainty of evidence. Overall, these studies reported improvements in clinical outcomes after RT. However, these findings need to be interpreted with caution. The challenges of inferring causality from single group designs are exemplified by the literature on RT for osteoarthritis. Two RCTs found no clinical or statistically significant difference in outcomes between patients randomized to RT or sham RT. However, 3 single group studies found clinically and statistically significant improvements in outcomes after RT. When relying on single group studies, it is challenging to differentiate treatment effect from symptom resolution that could have occurred naturally over the study observation period.

RT for the 9 prioritized diseases is generally used after conventional therapy fails. The referral practice of the primary provider treating the disease is a key factor in determining whether a patient receives RT. Although we did not extract data on referral networks, no study explicitly described how patients were referred to RT. For RT to become part of the standard care for the 9 prioritized diseases will require educating referring providers on the benefits and harms of RT. One of the biggest concerns for patients and providers when considering RT is the risk of radiation-induced secondary malignancies.^83^ This is especially a concern for younger patients.^10,84^ Most of the benign conditions we reviewed present later in life. Secondary malignancy can take years (10+) to occur and may be less of a concern of older patients. Finally, there were limited data on patient satisfaction, experience, or quality of life in most included studies.

## STRENGTHS AND LIMITATIONS OF THE EVIDENCE BASE

The evidence base on RT for the 9 prioritized diseases has several important limitations. First, only 6 of 9 diseases had any comparative data, and we were only able to evaluate certainty of evidence for 4 of 9 diseases. Further, only 1 disease category, heterotopic ossification, included evidence exclusively from RCTs. The lack of comparative data for much of the evidence base makes it challenging to determine the effect of RT compared to non-RT treatments. Most RCTs had independent outcome assessors but did not blind participants or personnel. Two RCTs evaluating RT for osteoarthritis and 1 for Ledderhose disease employed sham RT as a comparison group, which was a practical approach to ensure blinding of participants. Most of the NRCS reported unadjusted (ie, crude) results and did not adjust for confounding. Most diseases included single group studies, and there were many more single group studies that were eligible for analysis but not included in our synthesis (Appendix B-2). Although the single group studies are unable to determine the effect of RT on outcomes, if sufficiently powered they could provide insight into some adverse events including radiation-induced secondary malignancies. Unfortunately, many of the single group studies had small sample sizes and relatively short follow-up.

Second, there was substantial methodological variation between studies, both within and across diseases. This included variation in inclusion and exclusion criteria. Some studies included patients with a history of the disease of interests, and others only included incident cases. Within each disease category there was often meaningful variation in total radiation dose. There was also variation in the timing of when radiation was administrated (ie, before or after surgery). Further, comparator groups (when included) varied and included sham radiation, other active treatments, or other adjuvant treatments. Finally, there was wide variation in follow-up assessment across studies (1 to 144 months). Together, the differences across studies (both within and between diseases) makes it difficult to determine the effect of radiation on outcomes.

Third, inconsistent reporting of sample characteristics and outcomes limited interpretation of findings. Studies inconsistently reported disease characteristics before RT (eg, lesion size or duration of symptoms) and often did not report data on race or ethnicity. Most studies reported disease-related outcomes, but studies often did not use the same definition or measure to assess the outcome. Sometimes the measure or definition of an outcome was not clearly reported. In addition, studies did not clearly report whether they examined incidence or recurrence of disease. This was exemplified in the heterotopic ossification literature. Studies did not systematically report side effects. In addition, it was often unclear whether reported side effects were a secondary unintended consequence of the RT, the co-occurring intervention (eg, surgery), or a disease-related outcome. Radiation-induced cancer is a major concern of clinicians and patients, and no study reported any cases of secondary cancer, but no study was powered to detect this outcome. Finally, few studies reported patient quality of life, satisfaction, or experience.

## IMPLICATIONS FOR VA POLICY AND PRACTICE

None of the articles included in this review focused on a Veteran or military population. Many of the clinical diagnoses reviewed here likely translate to the VA population because the underlying biology and mechanisms of action of these conditions do not differ by patient population. Providers and Veterans are left with limited options when the prioritized conditions are resistant to conventional therapy. Although there are limitations to the evidence base, we found no indication that RT should not be used for the 9 prioritized diseases after conventional therapy fails. We therefore assess that there is equipoise about the clinical utility of RT in patients failing conventional therapies. This means that better-controlled comparative data are needed to determine the effect of RT on outcomes and whether low-dose RT provides value (ie, is cost effective from a VA or a health care sector perspective).

In the absence of ongoing RCTs, it may be practical to first accumulate observations within the VA setting by assembling a cohort of consecutive patients who meet criteria. As long as VA RT protocols are prospectively standardized, it should be possible to use the wealth of data in VA records to compare patients who were treated with RT with similar patients who did not receive RT using causally explicit analyses. A practical problem in such situations is to enroll enough people. There are opportunities for VA to learn from Germany, where 10-30% of RT is applied to treat benign conditions. To increase the uptake of RT, the VA can take the lead in developing guidelines on the use of RT, educate specialists about RT, and develop a benign disease care pathway to RT.

Few studies reported data on patient satisfaction or experience with care. These measures are more sensitive to health system structure, and it is unknown how Veterans would rate their experience with RT for benign diseases. There are 41 VHA-operated radiation oncology centers across the nation. Although VHA radiation oncology centers are strategically located, some Veterans may live closer to community oncology centers.^85^ Where Veterans receive care impacts their experience and quality of care, with a recent systematic review finding that care in the VA is either the same or better than the community.^86^

Furthermore, there are the limited data on radiation-induced secondary malignancies. VA has an opportunity to help fill these critical evidence gaps by drawing on past experiences in developing quality measures for cancer care. For example, the VA National Radiation Oncology Program (VA-NROP) invested in infrastructure to measure the quality and outcomes of cancer care.^87^ This has included consensus quality measures and dosing constraints for breast cancer,^88^ rectal cancer,^89^ prostate cancer,^90^ and head and neck cancer.^91^ A similar effort could be undertaken to measure quality and outcomes for benign disease treated by RT. To fill gaps on the effect of RT on radiation-induced secondary malignancies, VA could build off its medical record to develop a registry that includes information on site of the radiation for the begin disease and site of any follow-up cancer.

## RESEARCH GAPS/FUTURE RESEARCH

As noted above, many studies used a single group design. While a single group design can provide insight into changes that occur before and after treatment, it is challenging to disentangle the natural evolution of a disease from the effect of treatment. Thus, there is a need for well-designed, adequately powered comparative studies. Three RCTs employed sham radiation as the comparison group, which can serve as a useful model for future trials. Most observational studies used data from medical records, but they did not account for confounding between groups. Future NRCS should make use of an explicit causal inference framework and account for likely confounders of treatment effects by incorporating patient demographic, clinical, and prior treatment characteristics into analyses. There is also a need to better understand patient quality of life, experience, and satisfaction, including treatment-related burden, which should be collected with validated instruments. Although radiation-induced secondary malignancies are an extremely rare event, it is a concern of younger patients. To determine whether low-dose radiation causes cancer requires a large sample and long follow-up (20+ years). Administrative data, including the VA medical record, may provide a large sample size with sufficient follow-up, but these sources typically do not provide enough data on the anatomic site of radiation and cancer. Therefore, there is a need for the creation of a registry that follows patients after radiation. Finally, there is a need for the development of a benign disease care pathway so that referring providers are aware of RT as a treatment for when conventional therapy fails.

## STRENGTHS AND LIMITATIONS OF THE REVIEW PROCESS

Our review represents the most up-to-date evaluation of evidence on the use of low-dose RT for the treatment of 9 benign diseases. A strength of our review was the focus on a large number of diseases that are candidates for RT when conventional therapy fails and meta-analyzing findings for 3 of these diseases. This evidence review has several limitations. We employed a best-evidence approach to assess the effect of RT due to the large number of prioritized diseases and large number of published studies. This method allowed the strongest available evidence to be included in the synthesis of the literature (ie, comparative designs prioritized over single group studies). Nevertheless, we may have excluded studies with important data on the benefits and harms of RT for benign conditions. Furthermore, there was large variation in studies, and we were unable to investigate potential sources of heterogeneity of treatment effects (eg, effect of RT dose) because of small numbers of studies within a given disease. At times it was unclear whether an adverse event was actually a negative consequence of the treatment (ie, RT) or a feature of the lesions. We sought to limit inference about adverse events and therefore described these events as they were reported in the literature. Finally, several studies compared different radiation doses, which we treated as single group analyses because our key question was on the effect of RT relative to non-RT treatment.

## CONCLUSIONS

RT has been explored as a secondary treatment option for a variety of benign inflammatory and degenerative musculoskeletal conditions. In comparative studies, we found that RT may reduce the occurrence of heterotopic ossification and improve function in plantar fasciitis. There was no significant difference in pain for people with keloids. We have low confidence in these findings due to methodological limitations and imprecise and inconsistent estimates. One RCT found pain, walking speed, step rate, and quality of life improved for people with Ledderhose disease after RT compared to sham RT (certainty of evidence was not evaluated). Aside from these, there was either insufficient (due to no comparative design, methodological limitations, inconsistent estimates) or no evidence for the effect of RT on disease-related outcomes, side effects, or patient satisfaction, experience, or quality of life for people with keloids, pterygium, osteoarthritis, Peyronie’s disease, Dupuytren’s contracture, and hidradenitis suppurativa. Although there are gaps in the evidence, we found no indication that RT should not be used after conventional therapy fails for the 9 prioritized diseases. We therefore assess that there is equipoise about the clinical utility of RT in patients failing conventional therapies. High-quality comparative studies (RCTs or NRCS that account for likely confounders) are needed to clarify whether RT is beneficial for benign conditions.