# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from VHA National Radiation Oncology Program and our Technical Expert Panel (TEP) to refine the review scope and develop the key question (KQ). We focused on studies that reported on low-dose RT (<60 Gy) for the prevention or management of heterotopic ossification, keloid scars, plantar fasciitis, pterygium, osteoarthritis, Peyronie’s disease, Dupuytren’s contracture, Ledderhose disease, or hidradenitis suppurativa. These 9 conditions were selected because RT has been postulated to be an effective treatment for them, they are known to impact the Veteran population, and they could be addressed jointly given available resources. We excluded studies that did not use external radiation for all diseases except for pterygium, for which we also included radiation with brachytherapy. We evaluated the effect of RT on disease-related symptoms (eg, function for people with heterotopic ossification), side effects, and patient-centered outcomes (eg, quality of life, satisfaction, and experience).

## KEY QUESTIONS AND PROTOCOL

The following key question was the focus of this review:

Key Question | What are the benefits and harms of low-dose radiation therapy for the treatment or prevention of benign hyperproliferative and degenerative skin/epithelial, and musculoskeletal disorders such as keloid scars, hidradenitis suppurativa, Dupuytren’s contracture, Ledderhose disease, Peyronie’s disease, plantar fasciitis, heterotopic ossification, pterygium, or osteoarthritis in adults?

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023447241 (https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=447241)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in Appendix M.

## SEARCHING AND STUDY SELECTION

We searched Medline (via PubMed), Embase, and ClinicalTrials.gov from inception to April 1, 2023. We used Medical Subject Headings (MeSH) and free text terms relevant to the conditions (eg, pterygium and keloid) and radiation therapy (eg, radiation, radiotherapy, and electron beam). We ensured that known relevant publications were captured by our searches. Additional citations were sought from hand-searching reference lists of relevant systematic reviews and consultation with content experts. We identified a high quality published systematic review on the use of RT for osteoarthritis with search dates from inception to April 20, 2015; we relied on this review to identify eligible studies within its search period and updated its search to identify studies published later than April 2015. See Appendix A for complete search strategies.

Citations were uploaded into EndNote and duplicates were removed. We screened citations in Abstrackr (http://abstrackr.cebm.brown.edu),^31^ which has machine learning algorithms to prioritize relevant citations. To ensure a common understanding of the eligibility criteria, we ran pilot rounds of 500 citations at a time, where all team members screened the same citations, until we achieved acceptable agreement. Subsequently, we screened citations in duplicate with conflicts adjudicated during team meetings or by a third senior researcher. Based on empirical evidence, we stopped screening when all remaining unscreened abstracts had a prediction score of <0.40 (on a 0–1 scale), and subsequently 400 abstracts in a row were rejected.^31^ Accepted abstracts underwent full-text review using an evidence mapping process independently by 1 researcher with confirmation of excluded articles by a second researcher. When necessary, the reviewers consulted a third senior researcher. A list of studies excluded at full-text review, with rejection reasons, is provided in Appendix B-1.

Study eligibility criteria are shown in Table 1. In brief, eligible study participants were ≥18 years of age treated with low-dose RT (<60 Gy) for a benign condition of interest (eg, heterotopic ossification). We included all types of ionizing radiation (eg, photons, electrons, hadrons) delivered externally via photon or heavier particle beams. Studies not using external ionizing radiation (eg, studies using brachytherapy) were generally excluded. The exception was brachytherapy for the management of pterygium, which was included because it is the main mode of radiation dose delivery in the treatment of pterygium. We excluded studies where the majority of patients received re-irradiation of the same anatomic site. Due to the changes in radiation treatment over time, we excluded studies that treated patients before 1980. For studies that included a portion of patients treated before this date, exclusion applied if the majority of patients would have been treated before 1980, assuming equal number of patients per year. We followed a best evidence approach and prioritized comparative studies (ie, using RT vs not using RT) within each condition of interest.^32^ Randomized controlled trials (RCTs) were given priority over nonrandomized comparative studies (NRCS) and other comparative observational studies, whether prospective or retrospective, and regardless of whether they were adjusted for potential confounders. We only included single group studies when there were fewer than 5 comparative studies within a disease. In diseases with only single group studies, we reviewed those studies with the largest sample sizes (on average no more than 5 per condition, based on project budget). Appendix B-2 presents eligible studies that were not extracted following the best evidence approach.

Table 1 Inclusion and Exclusion Criteria

| Inclusion Criteria | Exclusion Criteria
Population | Adults ≥18 years of age with heterotopic ossification, keloid scars, plantar fasciitis, pterygium, osteoarthritis, Peyronie’s disease, Dupuytren’s contracture, Ledderhose disease, or hidradenitis suppurativa | Cancer; Nonmalignant tumors in head, neck, or brain.; Central nervous system conditions; Neurofibromatosis I and II; Pre-cancerous conditions of the skin (eg, Bowen’s disease); Patients receiving re-irradiation of same anatomic location; Not alive
Intervention | Photon, electron (beta particle), alpha particle therapy, or other hadrons (positively charged particles) for treatment, recurrence, or prevention; Only include brachytherapy for pterygium; <60 Gy | Non-ionizing radiation and re-irradiation
Comparator | Sham radiation therapy; Alternative treatments that do not include radiation; No treatment | Alternative dose of RT
Outcomes | Disease-related symptoms (eg, pain, stiffness, ambulatory status, appearance of tissue, recurrence of lesion, control of symptoms, and physical function); Local (short-term) side effects (eg, skin irritation, discoloration, scarring, edema, fatigue, nausea, alopecia, anemia, atrophy); Patient satisfaction/experience or quality of life; Burden related to accessing treatment (eg, wait time, distance traveled, travel cost)
Timing | Any
Setting | Any
Study Design | Best evidence approach prioritizing comparative studies; RCT; Nonrandomized comparative study, prospective or retrospective; Single group study^a^ | Does not report patient level data; Sample size ≤10 (among those receiving eligible treatment); Published before 1980; Reviews, editorials, opinion

Notes.

a A study that evaluates distinct interventions that all include radiation therapy and does not inform on the treatment effect of using versus not using radiation therapy.

Abbreviations. Gy=gray; RCT=randomized controlled study; RT=radiation treatment.

## DATA ABSTRACTION AND ASSESSMENT

We created a data extraction form in the Systematic Review Data Repository-Plus (SRDR+) online system (https://srdrplus.ahrq.gov). We extracted the following data from eligible studies: study design, setting, baseline population characteristics, total RT dose, duration of follow-up, disease-related symptoms, side effects, and patient-reported outcomes (eg, quality of life and satisfaction). All data extraction was first completed by 1 reviewer and then checked by a second reviewer. Disagreements were resolved by consensus or discussion with a third reviewer.

Study risk of bias was independently assessed by 1 reviewer and confirmed by a second using questions derived from the Cochrane Risk of Bias and the ROBINS-I (Risk Of Bias In Non-randomized Studies – of Interventions) tools (Appendix C).^33,34^ In addition, we used AMSTAR-2 to evaluate the quality of the osteoarthritis systematic review. For all study designs, we also evaluated whether the article was free of discrepancies, and reporting of patient eligibility criteria, protocols, setting, and outcome assessments was sufficiently clear. For RCTs, we evaluated the method of randomization, allocation concealment, and whether intention-to-treat analysis was used. For NRCS, we evaluated whether patients in the treated and comparison groups were similar and what strategies were used to deal with confounders. Single group studies do not directly inform on the treatment effect of using versus not using RT. Therefore, these studies had high risk of bias to determine the effect of RT on outcomes.

## SYNTHESIS AND CERTAINTY OF EVIDENCE

We compared results in study groups using odds ratios (OR) for dichotomous outcomes. When a study had 0 events in one group, we calculated risk differences (RD). We compared continuous data using net mean differences (ie, difference-in-differences or between-intervention comparisons of within-intervention changes from baseline to follow-up) or mean differences (MD) between interventions for outcomes evaluated only post-intervention. Adjusted analyses were preferentially extracted over unadjusted (crude) comparisons. Where there were at least 3 studies reporting results from similar analyses (based on population, interventions, comparators, and outcomes), we conducted random effects meta-analyses using the restricted maximum-likelihood (REML) estimator for the variance of the random effects, as implemented in the “meta” package for R version 4.3.0 (2023-04-21). Statistical heterogeneity was estimated using the I^2^ statistic, which estimates the percentage of heterogeneity ascribed to statistical heterogeneity (not ascribed to chance). In some cases, a 3-arm trial (eg, comparing an RT arm vs 2 non-RT interventions) contributed 2 comparisons in a meta-analysis. These comparisons have 1 arm in common (the RT arm in the example), which induces correlation in the estimates of the treatment effect. Such RCTs were represented in a meta-analysis as 2 independent trials in which the RT arm had half the sample size but the same proportion of events (for categorical outcomes) or the same mean outcome (for continuous outcomes). Using this heuristic, results from a meta-analysis of independent trials are numerically similar to those from an analysis that explicitly models the correlation in the estimated treatment effects for the RT versus non-RT comparisons from this trial. This heuristic is mentioned in textbooks, including the Cochrane Handbook.

When there were at least 3 comparative studies per disease, we assessed the certainty of evidence following the GRADE (Grading of Recommendations Assessment, Development and Evaluation) approach.^35^ We compiled key study findings in evidence profiles, which provide the basis for determination of certainty of evidence and summarize conclusions for outcomes. Within each outcome, we considered the study design, the number of studies and participants, methodological limitations, directness of the evidence, precision of the findings, consistency across studies, and other issues.

The precision of effect estimates were used to assess the clinical significance of treatment effects. First, when an estimate’s 95% confidence interval (CI) included large effects in both directions—for an OR, a CI with a lower bound <0.7 and a higher bound >1.4—we judged the estimate to be too imprecise to draw conclusions for the magnitude or even the direction of the true treatment effect. This scenario is illustrated in the bottom row of Figure 1. In other cases, we considered where the effect estimate and its CI fell relative to a narrow range around the null effect (ie, no difference between treatments), which we refer to as the zone of clinical indifference. For an OR, this range was between 0.9 and 1.1.

As illustrated in the first row of Figure 1, when an effect estimate and its CI were fully within the range of clinical indifference, RT was considered clinically equivalent to the treatment provided in the comparison condition (ie, no better or worse). In contrast, when the effect estimate and its CI were fully outside of the range and in the direction of benefit of RT (second row of Figure 1), RT was considered clinically superior to the comparison treatment. The final scenario was when an effect estimate was fully outside of the zone of clinical indifference and in the direction of benefit of RT, but was accompanied by a CI whose upper or lower bound fell within the zone of clinical indifference (third row of Figure 1). In this case, the true effect of RT could either be equivalent to the comparison treatment (if the true difference between treatments was in fact trivial) or superior to the comparison treatment (if the effect had been estimated with greater precision). An extension of the latter case was when the lower bound of the CI encompassed the null effect (1 for an OR), again as shown in the third row of Figure 1. Here, the effect of RT would be statistically nonsignificant but potentially clinically significant. The above scenarios are not exhaustive, but correspond to results encountered in this report.

Figure 1 Precision of Statistical Estimates and Range of Clinically Important Effects