# BACKGROUND

Radiation therapy (RT) is a standard part of care for many types of cancer.^1,2^ Radiation can shrink tumor size or inhibit tumor growth by causing cancer cell death or senescence through its effect on DNA damage.^3–5^ While RT is most frequently utilized for cancer treatment, low-dose RT has also been explored as a treatment for a variety of noncancerous inflammatory and degenerative musculoskeletal, orthopedic, and soft tissue diseases, typically after conventional medical treatments fail.^6–10^ This includes the use of prophylactic RT for the prevention of heterotopic ossification after hip replacement^7^ and keloids after surgical resection,^9^ as well as the treatment of painful inflammatory diseases such as osteoarthritis and plantar fasciitis.^11,12^

RT is commonly used for benign inflammatory and degenerative musculoskeletal diseases in Germany, where an estimated 10-30% of RT is applied to people with noncancer conditions.^13–16^ However, outside of Germany, RT is rarely used to treat benign conditions. The German Society of Radiation Oncology (DEGRO) S2e Consensus Guideline Radiation Therapy of Benign Diseases states that low-dose RT (between 3 and 6 Gy) for degenerative musculoskeletal disease is a reasonable approach when simple and non-invasive methods have failed.^17^

Benign inflammatory and degenerative musculoskeletal diseases can cause physical limitations, depression and anxiety, financial burden, and decreased quality of life.^18–22^ Veterans are at increased risk for some benign inflammatory and degenerative musculoskeletal, orthopedic, and soft tissue conditions due to the physical demands and injuries related to military service. For example, between 60-95% of Veterans experience heterotopic ossification following combat-related injuries.^23–27^ Similarly, a population-based study using Behavioral Risk Factor Surveillance System data found that arthritis was more prevalent in Veterans compared to non-Veterans (31.5% vs 22.1%).^28^ Another study reported that overuse injuries, such as plantar fasciitis, are common among US military personnel.^29^ Importantly, minority and woman Veterans are more likely to experience some inflammatory and degenerative musculoskeletal conditions. One study using data from the Defense Medical Epidemiology Database found that women and Black service members were significantly more likely than men and White service members to have plantar fasciitis (adjusted incidence rate ratio 1.95, 95% CI [1.94, 1.99] and 1.12, 95% CI [1.09, 1.12], respectively).^30^

Low-dose RT may be an effective treatment option for Veterans with a number of benign conditions resistant to conventional treatments. However, studies on the use of RT for benign conditions common in the Veteran population offer conflicting results about its effectiveness and potential adverse consequences. To inform guidance on the use of RT for benign conditions among Veterans, the Veterans Health Administration (VHA) National Radiation Oncology Program requested the following systematic review on the benefits and harms of low-dose RT for the treatment or prevention of benign hyperproliferative and degenerative skin/epithelial and musculoskeletal disorders.