# APPENDIX M PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
5 | 1 | No | Thank you.
6 | 2 | No | Thank you.
7 | 3 | No | Thank you.
8 | 4 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
9 | 1 | No | Thank you.
10 | 2 | No | Thank you.
11 | 3 | No | Thank you.
12 | 4 | Yes - Although published one month past literature search end date, phase III randomized LedRad-study provides significant impact to evidence of RT in Ledderhose disease and should be considered. PMID: 37211283 | Thank you. We have incorporated this study in the report and updated the summary statement. Note that we do not evaluate certainty of evidence for Ledderhose disease because this disease had less than 3 comparative studies.
Additional suggestions or comments can be provided below.
13 | 1 | This review offers a lengthy, organized, and detailed summary of low-dose radiation therapy (RT) for benign conditions, with a specific focus on those affecting veterans. Conducted by the Veterans Affairs (VA) Evidence Synthesis Program, the systematic analysis outlines the purpose, background, methods, and initial results. In the introduction, the purpose is clearly stated, detailing the specific request from the Veterans Health Administration and explaining how the evidence review aims to inform guidance on RT for benign conditions among veterans. The background section supports the rationale for the review, offering a comprehensive overview of RT’s use for various benign conditions and justifying the exploration of low-dose RT as an alternative treatment, particularly for musculoskeletal conditions among veterans. | Thank you.
14 | 1 | The methods section is detailed and transparent, explaining topic development, key questions, and protocol registration, enhancing the review’s credibility. Clear definitions of inclusion and exclusion criteria contribute to the transparency of the study selection process. The search strategy is well-described, indicating the databases searched and the time frame covered. The use of abstracts for citation screening and an explanation of the screening process add transparency to the study selection. The section on data abstraction and risk of bias assessment is thorough, outlining the process and tools used for evaluating study quality. The discussion of risk of bias assessment for different study designs adds depth to the evaluation. The synthesis section provides a comprehensive overview of included studies, employing meta-analysis and considering factors like statistical heterogeneity to strengthen the analysis. | Thank you.
15 | 1 | Emphasizing the certainty of evidence for each conclusion would enhance readers’ understanding of the findings’ robustness and study limitations. | The methods describes our approach for assessing certainty of evidence. Specifically, we assessed certainty of evidence when there were at least 3 comparative studies per disease (ie, heterotopic ossification, keloids, plantar fasciitis, and pterygium with brachytherapy). The text and key findings note when certainty of evidence was not assessed.
16 | 1 | The results discussion offers a comprehensive overview of studies on low-dose RT for various benign musculoskeletal conditions. While the conclusion is succinct and summarizes key findings, reinforcing the implications for clinical practice and policy would strengthen its impact. | Thank you.
17 | 1 | The discussion is well-structured, providing a comprehensive overview of studies examining the use of low-dose RT for various benign conditions. The text is skillfully organized with clear headings and subheadings, facilitating an easy understanding of the review’s structure. The separation of purpose, background, methods, and results enhances readability.; In conclusion, I find this manuscript to be well-organized, presenting information in a clear and structured manner. It comprehensively addresses various diseases, offering a thorough overview of studies conducted on each condition. The document outlines the review’s methodologies, including search and eligibility criteria, and data analysis methods. Incorporating diverse study types such as RCTs, NRCS, single-group studies, and systematic reviews broadens the perspective on existing literature. The meticulous evaluation of each condition, along with a summary of findings, enhances the overall clarity of the review. Results are presented lucidly, with the inclusion of tables and figures for better comprehension. Furthermore, the incorporation of a sensitivity analysis and examination of historical comparison groups adds nuance to result interpretation. Emphasizing the necessity for high-quality comparative studies and highlighting the VA’s potential leadership in developing RT guidelines for benign diseases is crucial. | Thank you.
18 | 1 | Minor suggestions:; Although the review acknowledges limitations, including potential biases, variability in RT doses, and limited availability of high-quality evidence, explicitly stating the certainty of evidence for each discussed condition would be beneficial. While some diseases mention certainty of evidence, others lack this clarification. | We evaluated certainty of evidence when there were at least 3 comparative studies per disease (ie, heterotopic ossification, keloids, plantar fasciitis, and pterygium with brachytherapy). The text and key findings note when certainty of evidence was not assessed.
19 | 1 | When discussing methodological concerns, specify what these concerns might mean for the reliability and validity of the study results. | Thank you. We revised the risk of bias descriptions to comment on the relevant concerns for reliability and validity of the study results.
20 | 1 | Additionally, expanding the discussion section to elaborate further on the potential implications for VA policy and practice and provide more context on findings’ implications, potential clinical applications, and future research areas focusing on conditions affecting veterans would be valuable. Suggest recommendations for how the VA can integrate low-dose RT into its care strategies for these conditions. | We expanded the discussion section to provide more context on the potential implications for VA policy and practice.
21 | 1 | There are a few typos, some of which are listed below:; P9, L41: “Clincally”; P21, L37: “reccurece”; P22, line 50, “scare”; P25, L26: “inonsistent”; P25, L37: “inconsistat”; P25, L43: “consistant”; P25, L56: “treatement”; P30, L22: “reccurece”; P45, L3: “condtions”; Appendix D, table row= Ince, 2007: “osteoartritis”; Appendix D2, table row=Kolbl 1998: “indomethacin”; Appendix D2, table row=last: “contralateraly”; Appendix E4, row=Qiao 2017: “Criterai”; Appendix F2, bottom legend: “megaboltage”; Appendix G2, row=Simsek 2001: “Pterigium” “Anteneoplastic”; Appendix G4, row=Simsek, 2001: “Lense”; Appendix J2, row=Adamietz 2001: “orthovoltae devide”; Appendix K2, row=Seegenschmiedt 2003: “orthovoltae devide”; Appendix J4, row= Adamietz 2001: “teleangiectasia”; Appendix K4, bottom legend: “toxity” | Thank you. We revised the typos.
22 | 2 | page iv, line 26; remove common between James and Rudolph; page v, line 49; remove Radiation Oncology (redundant with Chief, Radiotherapy on line above); page vi, line 13, Dr. Wolfson’s title is Professor; page vi, line 14, Dr. Wolfson is in the “Department of Radiation Oncology, University of Miami”; page viii, line 54 remove “and" before keloids; page xiii, line 57 “can also be used to treat”; page xiv, line 57 “radiation-induced secondary malignancies”; page 3, line 34 “platelet-rich plasma therapy”; page 4, line 49 “US military personnel.”; page 9 line 42 “range of clinically important effects”; page 13, line 38; the numbers in the row do not add up to 26; page 13, line 44, the numbers in the row do not add up to 21; page 18, line 16 “In contrast, 1 RCT…”; page 21, line 37 “Figure 4. Keloid recurrence at follow up:”; page 24, line 52 “no significant difference in plantar fasciitis”; page 26, line 12 “compared to PGSI”; page 30, line 17 “brachytherapy (10-70 Gy)”; page 39, line 29 “Tubiana et al’s staging methodology”; page 40, line 53 “co-occurring related diseases”; page 42, line 50 “Side effects and patient”; page 45, line 11 “improved function for people” | Thank you. We have fixed these typos.
23 | 2 | page 19, lines 8-10, given that the focus is adjuvant RT for keloids, should the NCRS that compares RT to surgery be included? | Thank you. The primary meta-analysis of keloids now excludes the NRCS. In a post hos sensitivity analysis, we included the NRCS in the meta-analysis and note this did not alter our conclusions.
24 | 3 | No comments. | Thank you.
25 | 4 | Overall, excellent summation of the strength of literature for LDRT in various benign conditions. Provided excellent example for need for further high quality research of the use of LDRT for benign diseases. Below are a few suggestions: | Thank you.
26 | 4 | Page Xii; Line 10- would be helpful to describe how brachytherapy was prescribed and what isotope used if available. | Appendix G-2 now reports the isotopes used in each study employing brachytherapy. During the development of our study protocol, we were guided by the Technical Expert Panel and partners to only report the total Gy.
27 | 4 | Page Xiii; Line 27- Randomized blind phase 3 study published in May 2023 shows significant benefit of RT versus sham providing high level evidence of efficacy. While outside literature search by 1 month, would be disservice to not include given level of evidence doi: 10.1016/j.radonc.2023.109718 | Thank you. We have incorporated this study in the report and updated the summary statement. Note that we do not evaluate certainty of evidence for Ledderhose disease because there were less than 3 comparative studies.
28 | 4 | Page XIV; Line 51- In addition to sham, could consider comparison to other conservative modalities such as steroid injections, NSAIDs, etc. | Thank you. We incorporated this suggestion in the Discussion.
29 | 4 | Page XV; Line 30- Ledderhose conclusion should be re-evaluated in light of recent positive phase 3 data | We revised the summary statement for Ledderhose to reflect the findings from the RCT.; “In summary, 1 RCT and 3 single group studies reported pain and walking improved after RT. The RCT reported quality of life improved after RT. Lesions and symptoms stabilized and nodes and strands decreased after RT. Side effects included skin irritation (13% to 20%) and erythema (3% to 25%). Most patients were satisfied with their treatment at follow up. Certainty of evidence was not assessed for these outcomes. Appendix K-4 presents detailed outcome data.”
30 | 4 | Page 4; Line33- Estimated that over one-third all RT in Germany is for benign disease doi:10.1259/bjr.20150080 | The study (Seegenschmiedt 2015) noted by the reviewer states: “Non-malignant indications for RT comprise about 10–30% of all treated patients in most academic, public and private RT facilities in Germany.” We revised the introduction to note that 10-30% of RT in Germany is applied to people with noncancer conditions.
31 | 4 | Page 26; Line 24- *von Pannewtiz score (VPS) | Thank you.
32 | 4 | Page 33; Line 16-*von Pannewtiz score (VPS) | Thank you.
33 | 4 | Page 40; Line 36- Randomized blind phase 3 study published in May 2023 shows significant benefit of RT versus sham providing high level evidence of efficacy. While outside pubmed search by 1 month, would be disservice to not include given level of evidence doi: 10.1016/j.radonc.2023.109718 | Thank you. We have incorporated this RCT in our reported and updated our conclusions accordingly.
34 | | Page 45; Line 3- Estimated that over one-third all RT in Germany is for benign disease doi:10.1259/bjr.20150080 | Thank you. Please see our response to comment #29.