# APPENDIX L HIDRADENITIS SUPPURATIVA

## APPENDIX L-1 HIDRADENITIS SUPPURATIVA DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Fröhlich 2000, 10897256 Germany | Single Group | 1979-1997 | 2 hospitals (unclear level of care) | Primary treatment as first line or later line therapy | Patients with axillary hidradenitis suppurativa | NR

Abbreviations. NR=not reported; PMID: PubMed ID; RT=radiation therapy.

## APPENDIX L-2 HIDRADENITIS SUPPURATIVA BASELINE DATA

Author, Year, PMID | N Patients | Treatment | N Lesions | Age | N (%) Male | N (%) White | Lesion Characteristics
Author, Year, PMID | N Patients | Treatment | N Lesions | Age | N (%) Male | N (%) White | Location | Lesion Age | Symptoms and Severity | Previous Treatment | Comorbidities
Froehlich 2000, 10897256 | RT = 231 | Linear accelerator X rays, 175KeV.; Acute cases treated 0.5G, up to 5 days/week frequency for a total of 3 Gy; Chronic cases treated with up to 1.5Gy per dose, up to 3 day per week frequency for a total dose of up to 8 Gy.; Most patients (n=190) received 6 doses; 9 patients more than 8 and up to 10 Gy; For 34 patients with persisting symptoms after 6 weeks, a second series was done (total dose 20 Gy in both series). | 270 | Median about 40y (range 20, 79) | 58 | NR | Axilla (right 43%, left 40%, both 17%) | Less than 1 week (n=95, 41%); 1 to 2 weeks (n=47, 20%); 2 weeks to 1 month (n=42, 18%) | Pain (n=65, 28%); Induration (n=67, 29%); Redness (n=13, 6%),; Full manifestation (n=79, 34%); Severity^*^; Beginning (n=95, 41%),; Coarse nodular with coarse glandular swellings (n=21, 9%); Advanced form with gross nodular swelling of the glands and abscess formation (n=18, 8%),; Chronic recurrent hidradenitis with inflammation of the skin (n=92, 40%).; Phlegmonous hidradenitis with spread of the inflammation into the depth of the armpit (n=5, 2%). | None (n=105, 45%); Drainage (n=90, 39%); Antibiotics (n=16, 7%); Antibiotics and ointments (n=20, 17%) | NR

Notes.

* Per Dornuf et al: Dornuf G. Schönwald H. Zur Röntgentherapie der sogenannten Schweißdrüsenabscesse. Strahlentherapie 1951:84:439–48 14835098 .

Abbreviations. Gy=gray; KeV=kilo-electrovolt; NR=not reported; RT=radiation therapy; SD=standard deviation.

## APPENDIX L-3 HIDRADENITIS SUPPURATIVA QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall RoB
Froehlich 2000, 10897256 | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern | Yes (Low concern | NA | NA | No (Low Concern) | High RoB (Single Group)^a^

Notes.

a The study design is unable to estimate the effect of RT on outcomes.

Abbreviations. ITT=intention-to-treat; NA=not applicable; NRCS=nonrandomized comparative study; RCT=randomized controlled trial.

## APPENDIX L-4 HIDRADENITIS SUPPURATIVA RESULTS SUMMARY

Author, Year, PMID | Comparator | Symptoms/Efficacy | Side Effects | Patient Satisfaction/Experience/QoL
Froehlich 2000, 10897256 | None; Follow-up 1 to 1.5 months. | Resolution of all symptoms:; 89/231 (39%); Resolution or improvement in symptoms; 181/231 (78%); Resolution via abscessation (with or without spontaneous drainage); 48/231 (21%); No improvement 2/231 (1%) | NR | NR

Abbreviations. CI=confidence interval; Mo=months; MD=mean difference; NR=not reported; PMID=PubMed ID; QoL=quality of life; RT=radiation therapy; SD=standard deviation.