# APPENDIX K LEDDERHOSE DISEASE

## APPENDIX K-1 LEDDERHOSE DISEASE DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
De Hann, 2023, 37211283, Netherlands | RCT | 2018-2019 | Multicenter | Primary treatment / prevention of recurrence | Adult patients (18 or over) with a WHO performance score 0-2, Pain score related to Ledderhose disease>= 2, good understanding of the Dutch language, ability and willingness to attend follow-up visits, and complete several questionnaires in Dutch. | Patients with previous RT treatment and/or surgery for Ledderhose disease in the affected foot, any psychological, familial, sociological or geographical condition potentially hampering compliance with the study protocol or follow-up schedule, unable to lie in a prone position for at least 15 minutes, pregnancy at entry or planning to become pregnant within 6 months.
de Hann 2022, 35101465 NCT04229147 Netherlands | Single Group | 2008-2017 | Teaching Hospital | Primary treatment / prevention of recurrence | Patients with Ledderhose who were treated with RT from 2008-2017 with a minimum of 2 years follow-up | NR
Heyd 2010, 20082184 Germany | Single Group | 2003-2008 | Other/Unclear | Primary treatment / prevention of recurrence | NR | Patients receiving a deviating RT protocol or with incomplete follow-up
Seegenschmiedt, 2003, 14652674 | Sigle group | 1996-2002 | Single clinic | Primary treatment/prevention of recurrence | Patients with ML (Morbus Ledderhose) | Patients with minor symptoms or very small nodes were not treated

Abbreviations. NR=not reported; PMID=PubMed ID; RT=radiation therapy.

## APPENDIX K-2 LEDDERHOSE DISEASE BASELINE DATA

Author, Year, PMID | N Patients | Intervention | N Lesions | Age (Years), Mean (SD) | N (%) Male | N (%) White | Location | Lesion Age | Size (mm) | Previous Treatment | Comorbidities
De Hann, 2023, 37211283 | RT = 42 | Five daily fractions of 3 Gy for 10 weeks for total dose of 30. | RT = 65 | 55.9 (9.4) | 57 (67.9) | NR | Foot | NR | NR | NR | NR
De Hann, 2023, 37211283 | Sham = 42 | The radiation therapy device was not activated, and patients were exposed to recordings of the sound of the device | RT = 65 | 55.9 (9.4) | 57 (67.9) | NR | Foot | NR | NR | NR | NR
de Hann 2022, 35101465 | RT = 67 | Participants received two courses of 5 daily fractions of 3 Gy repeated after 10 weeks for a total dose of 30 Gy. Patients were irradiated using either orthovolt (N = 9 feet) or electrons (N = 3 feet). | 102 | 55 (9.6); Mean (SD) | 28 (41.8) | NR | Foot (20 left; 12 right; 35 bilateral) | NR | NR | Received surgery for the disease prior to RT, N (%) = 13 (19.4); Re-irradiated on new nodules outside the previously treated area, N (%) = 1 (1.5) | Cooccurring disease, N (%):; Dupuytren’s disease = 40 (60%); Peyronie’s disease = 4 (6.0%); 50% of patients had a family history of Ledderhose, Dupuytren’s, and/or Peyronie’s disease
Heyd 2010, 20082184 | RT = 24 | Participants received either five weekly fractions of 3.0 Gy repeated at 6 weeks for a total dose of 30.0 Gy (N=20) or two fractions of 4.0 Gy on consecutive days, repeated every 4 weeks to a total dose of 24–32 Gy (N=4). Patients were irradiated using either orthovoltage X-ray (N=21) or electrons of a linear accelerator (N=3). | 33 | 52 (28-83); Mean (Range) | 12 (50) | NR | Foot (9 right, 6 left, 9 bilateral) | Persistence of complaints prior to RT was 2-60 months (Median= 9.5; Mean= 14.2) | NR | The majority of patients were previously treated by prescription of decompressive insoles or oral administration of nonsteroidal anti-inflammatory drugs.; In addition, 2 patients underwent surgery and RT was prescribed for treatment of recurrent disease. | Concomitant Morbus Dupuytren, N (%)= 10 (41.7)
Seegenschmiedt, 2003, 14652674 | RT = 25 | External beam: Total dose, 30 Gy, through10 fractions, 3 Gy per dose, 5 fractions per week, with 8-12 weeks interval using orthovoltage device (Philips, Hamburg, Gulmay Medical, Bristol, UK) 150-kv photon/20 mA/4-mm aluminum filter) | 36 | Median (range); 56 (9-76) | 13 (52) | NR | Right feet: 16 (44.4), Left feet: 20 (55.6) | NR | Nodes size: average 2.4 cm (range 0.5-6.5 cm); Strands length: average 2.5 cm (range 1-4 cm) | NR | Morbus Dupuytren 12 (48); typical knuckle pads: 2 (8); Induration penis plastica: 1 (4)

Abbreviations. Gy=gray; kV=kilovoltage; mA=milliamperes; NR=not reported; PMID=PubMed ID; RT=radiation therapy; SD=standard deviation.

## APPENDIX K-3 LEDDERHOSE DISEASE QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representative | Adjustment for confounders | Other bias | Overall RoB
De Hann, 2023, 37211283 | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Unclear | No (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Low (RCT)
de Hann 2022, 35101465, Single group | NA | NA | NA | No (High concern)^a^ | No (Low concern) | NA | MA | No (High concern)^b^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Unclear | NA | NA | No (Low concern) | High (Single group)^c^
Heyd 2010, 20082184, Single group | NA | NA | NA | Unclear | No (Low Concern) | NA | NA | Yes (Low concern | Yes (Low concern) | Yes (Low concern) | No (High concern)^d^ | Yes (Low concern) | NA | NA | No (Low concern) | High (Single group)^c^
Seegenschmiedt, 2003, 14652674 | NA | NA | NA | No (High concern)^e^ | No (Low Concern) | NA | NA | Yes (Low concern | Yes (Low concern) | Yes (Low concern) | No (High concern)^d^ | Unclear | | | No (Low concern) | High (Single group)^c^

Notes.

a Outcomes were self-reported;

b Unclear which measure was used when reporting pain outcomes;

c The study design is unable to estimate the effect of RT on outcomes

d Unclear definition of outcomes;

e Some outcomes were self-reported.

Abbreviations. NA=not applicable; NRCS=nonrandomized comparative study; RCT=randomized controlled trial.

## Appendix K-4 Ledderhose Disease Results Summary

Author, Year, PMID | Comparator | Symptoms/Efficacy | Side Effects | Patient Satisfaction/Experience/QoL
De Hann, 2023, 37211283 | RT vs Sham; Follow-up, mo = 6, 12, and 18 | Pain (NRS), M (SD); Baseline (N=42 vs 42); 5.8 (2.1) vs 5.6 (2.1); 6 mo follow-up (N=40 vs 40); 3.2 (2.6) vs 3.4 (2.5); Mean difference (95% CI):; −0.2 (−1.1 to 0.7); 12 mo follow-up (N=40 vs 39); 2.5 (2.5) vs 3.6 (3.0); Mean difference (95% CI):; −1.1 (−2.1 to −0.1); 18 mo follow-up (N=40 vs 39); 2.1 (2.3) vs 3.4 (2.8); Mean difference (95% CI):; −1.3 (−2.2 to −0.4); RT pain response (%); 6 mo follow-up (N=40); Progressive pain 5%; Stable pain 34%; Partial pain response 48%; Complete pain response 13%; 12 mo follow-up (N=40; Progressive pain 2%; Stable pain 24%; Partial pain response 37%; Complete pain response 37%; 18 mo follow-up (N=40; Progressive pain 5%; Stable pain 18%; Partial pain response 38%; Complete pain response 39%; Sham RT pain response (%); 6 mo follow-up (N=40); Progressive pain 5%; Stable pain 34%; Partial pain response 48%; Complete pain response 13%; 12 mo follow-up (N=39; Progressive pain 14%; Stable pain 30%; Partial pain response 39%; Complete pain response 17%; 18 mo follow-up (N=39); Progressive pain 9%; Stable pain 37%; Partial pain response 39%; Complete pain response 15%; Overall pain response (4 categories) significantly different (p = 0.002); Walking speed m/sec, M (SD); Baseline (N=42 vs 42); 1.53 (0.27) vs 1.56 (0.31); 6 mo follow-up (N=40 vs 40); 1.61 (0.27) vs 1.59 (0.26); Mean difference (95% CI):; 0.02 (−0.12 to 0.16); 12 mo follow-up (N=40 vs 39); 1.65 (0.23) vs 1.61 (0.26); Mean difference (95% CI):; 0.04 (−0.09 to 0.17); 18 mo follow-up (N=40 vs 39); 1.65 (0.26) vs 1.58 (0.30); Mean difference (95% CI):; 0.07 (−0.07 to 0.21); Step rate (steps/sec), M (SD); Baseline (N=42 vs 42); 2.18 (0.26) vs 2.24 (0.58); 6 mo follow-up (N=40 vs 40); 2.25 (0.27) vs 2.15 (0.23); Mean difference (95% CI):; 0.10 (−0.01 to 0.21); 12 mo follow-up (N=40 vs 39); 2.28 (0.28) vs 2.18 (0.21); Mean difference (95% CI):; −0.01 to 0.21); 18 mo follow-up (N=40 vs 39); 2.12(0.22) vs 2.25 (0.26); Mean difference (95% CI):; −0.13 (−0.24 to 0.02) | Adverse side effects; Erythema foot soles; 13 (33) vs 7 (18); OR (95%CI); 2.20 (0.77; 6.30); Dryness skin foot; 12 (30) vs 6 (15); OR (95%CI); 2.36 (0.78; 7.09); Increased pain; 10 (25) vs 8 (21); OR (95%CI); 1.29 (0.45; 3.72); Burning sensation; 7 (18) vs 7 (18); OR (95%CI); 0.97 (0.31; 3.08); Mental impact; 5 (13) vs 2 (5); OR (95%CI); 2.64 (0.48; 14.52); Fatigue; 5 (13) vs 4 (10); OR (95%CI); 1.25 (0.31; 5.05); Increased sensitivity; 4 (10) vs 3 (8); OR (95%CI); 1.33 (0.28; 6.39); Edema feet; 3 (8) vs 3 (8); OR (95%CI); 0.97 (0.18; 5.14); Tingling feeling; 1 (3) vs 3 (8); OR (95%CI); 0.31 (0.03; 3.09); Telangiectasia; 1 (3) vs 0 (0); Blisters; 1 (3) vs 0 (0); Other; 25 (63) vs 22 (56); OR (95%CI); 1.29 (0.52; 3.17); Serious adverse events; 1 (2) vs 2 (5); OR (95%CI); 0.47 (0.04; 5.45) | QoL (EQ D5), M (SD); Baseline (N=42 vs 42); 0.63 (NR) vs 0.71 (NR); 6 mo Follow-up (N=40 vs 40); 0.82 (NR) vs 0.77 (NR); 12 mo Follow-up (N=40 vs 39); 0.85 (NR) vs 0.77 (NR); 18 mo Follow-up (N=39 vs 40); 0.84 (NR) vs 0.76 (NR); Overall improvement more “pronounced” for patients who received RT (p <0.001); QoL (EQ VAS), M (SD); Baseline (N=42 vs 42); 71.9 (NR) vs 67.8 (NR); 6 mo Follow-up (N=40 vs 40); 74.8 (NR) vs 74.8 (NR); 12 mo Follow-up (N=40 vs 39); 76.8 (NR) vs 74.0 (NR); 18 mo Follow-up (N=40 vs 39); 78.8 (NR) vs 73.8 (NR); Overall improvement more “pronounced” for patients who received RT (p = 0.04)
de Hann 2022, 35101465 | Baseline vs follow-up^a^,; Follow-up (mo), median (range) = 49 (24-132) | Pain (LedRad-LTE)^b^ (N=102 feet), M (SD); Pre-RT = 5.7 (2.5); Follow-up = 1.7 (2.1); p<0.001; MD (CI) = −4 (−4.451, −3.549)^c^; Pain interference (Brief Pain Inventory) (N=102 feet), at follow-up, Mean (SD)=1.3 (1.8); Response to pain at follow-up (N=102 feet) (LedRad-LTE), N (%)^d^; Complete = 42 (41.2); Partial = 38 (37.3); No change = 22 (21.5); Progressive = 0 (0); Patient reporting a permanent positive effect of radiation therapy on pain (N=67 patients)^f^= 46 (69) | Long-term side effect, time not specified) (N=67 patients), N (%); Dryness = 10 (15); Erythema = 2 (3) | EURO-QOL-5D-5L- societal perspective at follow-up (N=64 patients), Mean (SD); Study sample [Mean (SD) 59.8 (9.7) years old] = 0.856 (0.130); Reference values of the Dutch general population (50-60 years old) = 0.857 (0.183); EURO-QOL-5D-5L- patient perspective at follow-up (N=64 patients), Mean (SD); Study sample [Mean (SD) 59.8 (9.7) years old] = 82.3 (14.5); Reference values of the Dutch general population (50-60 years old) = 80.6 (NR); Patient satisfaction with treatment (N=67 patients), N (%)^e.f^= 52 (78); Patients who considered treatment not burdensome (N=67 patients) m N (%)^f^= 38 (57)
Heyd 2010, 20082184 | Baseline vs follow-up; Follow-up (mo), median (range) = 22.5 (6-76) | Pain remission among those who experienced pain at baseline (N=19 patients), N (%)^g^ = 13 (68.4); Persistent pain (undefined) among those who experienced pain at baseline (N=19 patients), N (%); Slight = 4 (21.1); Moderate = 3 (15.8); Lesion Remission (undefined) (N = 33 lesions), N (%):; Complete = 11 (33.3); Partial^h^ = 18 (54.4); Stable = 4 (12.1); Progression of size and number of the lesions or clinical symptoms at follow-up (N=24), N (%) = 0 (0); Gait abnormality improvement among those with gait abnormalities at baseline (N=15 patients), N (%)^i^ = 11 (73.3); Gait normalization among those with gait abnormalities at baseline (N=15 patients), N (%)^i^ = 9 (60.0) | Erythema or hyperpigmentation (time not specified) (N=24 patients), N (%) = 6 (25); Soft tissue fibrosis and an increased dryness of the skin (time not specified) (N=24 patients), N (%) = 3 (12.5) | Improvement in subjective satisfaction of functional status (N=24 patients), N (%)^j^ = 22 (91.6)
Seegenschmiedt, 2003, 14652674 | Follow-up (mo), Median = 42 | Prevention of progression (N=36 lesions), N (%); = 36 (100); Decrease in one or more findings or symptoms (N = 25 patients), N (%); 20 (80); Physical function (Gait: Complete response); Patients N = 25, n/N (%) = 5/25 (20); Number of patients with gait disturbance; Before treatment = 8; After treatment = 3; Number of nodes; Before treatment = 63; After treatment = 46; Average decrease in size of nodes (cm) (N=63), Mean (range) = 1.5 (1-3); Number of strands:; Before treatment = 20; After treatment = 11; Average decrease length of strands (cm) (N =20), Mean (range) = 1.5 (1-2); Stable nodes (no node enlarged, or new nodes appeared) (N=25), N (%); 15 (60); Strands remained stable (N-25), N (%) = 15 (60); Disappearance of additional symptoms (swelling, pressure sensation) (N=12), N (%); 6 (50); Patients with remaining “tension sensation” (N=7), N (%); 6 (86); Patients reported improvement on VAS (N=25), N (%); Improved by 75-100% = 6 (24); Improved by 50-74% = 8 (32); Improved by 25-49% = 6 (24); No improvement/stable = 5 (20); Pain response (N=16), N (%); Complete response = 9 (56); Remained the same = 7 (44) | Skin redness (CTC concept) (N=25) [up to 3mo post RT] = 5 (20) | NR

Notes.

a Follow-up defined as time between last day of radiation and completion of questionnaire (months);

b Investigator developed, non-validated custom-made questionnaire;

c Numbers estimated by research team based on percentages presented in the article;

d Complete pain response (absence of pain)=current pain score of 0 points with decrease of the initial pain score by at least two points; partial pain response=current pain score of at least 1 point with a decrease of the initial pain score by at least 2 points; no change=1 or zero point change in either direction from initial pain score; progressive=increase in initial pain score by at least 2 points;

e Very satisfied to very unsatisfied;

f Total N not specified but assumed to be full sample;

g No, slight, moderate, severe;

h Classified as partial due to a reduced number or size of cords;

I No limitations, >1km, ≤1km, complete limitation;

j Using linear analog scale.

Abbreviations. CI=confidence interval; CTC=common toxicity criteria; EURO-QOL-5D-5L=European Quality of Life-5 Dimensions – 5 levels scale; MD=mean difference; LedRad-LTE=Ledderhose disease – Long Term Effects of Radiotherapy Treatment; Mo=months; NRS=numeric rating scale;NR=not reported; QoL=quality of life; RT=radiation therapy; SD=standard deviation.