# APPENDIX J DUPUYTREN’S CONTRACTURE

## APPENDIX J-1 DUPUYTREN’S CONTRACTURE DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Betz, 2010, 20127225, Germany | Single group | 1982-2006 | Teaching Hospital, Single center | Primary treatment / prevention of recurrence | Patients with clinically evident and progressive early-stage Dupuytren’s contracture. | NR
Keilholz, 1996, 8960518, Germany | Single group | 1982-1993 | Other/Unclear, NR / Unclear | Primary treatment / prevention of recurrence | Patients with clinically evident Dupuytren’s contracture. | NR
Latusek, 2017, Poland | Single group | NR | Other/Unclear, Single center | Primary treatment / prevention of recurrence | NR | NR
Zirbs, 2015, 25201324, Germany | Single group | 2009-2013 | Teaching Hospital, Single center | Primary treatment / prevention of recurrence | Patients with Dupuytren’s contracture treated between 1999 and 2008. | NR
Adamietz, 2001, 11757183 | Single group | 1982-1994 | Single Center | Primary treatment | Patient with Morbus Dupuytren | NR

Abbreviations. NR=not reported; PMID=PubMed ID; RT=radiation therapy.

## APPENDIX J-2 DUPUYTREN’S CONTRACTURE BASELINE DATA

Author, Year, PMID | N Patients | Intervention Characteristics | N Hands | Age | N (%) Male | N (%) White | Previous Treatment | Comorbidities | Other
Betz, 2010, 20127225, Germany | RT = 135 | Two separate courses of five daily fractions of 3Gy each to a total dose of 30Gy with 6 weeks between courses. | RT = 208 | NR | 127 (61.1) (hands)^a^ | NR | Patients who had received previous treatment (N = 135), N(%); 9 (6.7); Surgery and corticoid therapy. | Comorbidities (N = 208 hands), N (%)^a^; Ledderhose = 24 (11.5); Peyronies = 11 (5.3); Knuckle pads = 5 (2.4); Diabetes = 35 (16.8); Alcoholism = 9 (4.3) | Family history, N (%) = 78 (37.5%)^a^
Keilholz, 1996, 8960518, Germany | RT = 96 | Two courses of five fractions of 3Gy per fraction to a total dose of 30Gy with 6 weeks between courses | RT = 142 | 54.0 (14.0)^b^ | 66 (68.8)^a^ | NR | NR | Comorbidities (N = 96), N (%)^a^; Epilepsy = 2 (2.1); Diabetes = 11 (11.5); Alcoholism = 17 (17.7) | Family history (patients, N (%) = 33 (34.4)^a^; Stage, N (%)^d^; N = 82 (58); N/I = 17 (12); I = 30 (21); II = 12 (8); III = 1 (1); Duration of clinical symptoms before RT (years), mean = 8 +/− 4
Latusek, 2017, Poland | RT = 117 | Up to 21 Gy administered in 7 fractional doses. | RT = 180^a^ | 61^b^; 62 (30-82)^c^ | 78 (66.7)^a^ | NR | Patients who had received previous treatment (N = 117), N (%); 19 (16%)^a^; Laser therapy, surgical treatment, ultrasound, steroid | NR | History of smoking, N (%) = 68 (58)^a^; Smoked during treatment, N (%) = 23 (20)^a^
Zirbs, 2015, 25201324, Germany | RT = 206 | Four courses of 2 fraction of 4Gy per fraction to a total dose of 32Gy, with 8 weeks between courses. | RT = 297 | 62.9^c^ | 123 (59.7) | NR | Patients who had received previous treatment (N = 206), N (%); 37 (18%); Surgery, needle fasciotomy, local steroid injection, vitamins, shock-wave therapy, magnetic field therapy, massage, NSAID. | Comorbidities (N = 206), N(%); Ledderhose = 18 (8.7); Induration penis plastica = 13 (6.3); Knuckle pads = 18 (8.7); Keloids = 7 (3.4); Cardiovascular disease = 21 (10.2); Diabetes = 18 (8.7); Liver disease = 4 (1.9); Epilepsy =1 (0.5) | Patients reporting a positive family history of Dupuytren’s, (N = 206), N (%) = 59 (28.6); Disease Activity (not defined) (N =206), N (%); Slow progressive activity = 122 (59.2); Slow progression in batches = 23 (11.2); Rapid progression = 25 (12.1); Very rapid progression =14 (6.8)
Adamietz-2001-11757183 | 99 | External beam: Total dose, 30 Gy, through10 fractions, 3 Gy per dose, 5 fractions per week, with 6-8 weeks interval using orthovoltage device (Stabiliplan, Siemens, Erlangen, 120-kv photon/20 mAs/4-mm aluminum filter) | 176 | Median (range) 53.5 (18-70) | 66 (66.7) | NR | NR | Concomitant diseases 25 (25); Ledderhose disease 6 (6); Induratio penis plastica 1 (1); Diabetes mellitus 10 (10); Liver cirrhosis 2 (2); Condition after accident/hand injury 12 (12) | Family History 63 (63.6); Stages (N = 176 hands); 0: n = 5 (2.8); N: n = 76 (43.2); N/I: n = 15 (8.5); I: n = 65 (36.9); II: n = 12 (6.8); III: n = 3 (1.7)

Notes.

a Values calculated by the research team based on data provided in the article;

b Mean (SD);

c Median;

d N= nodes without flexion deformity; N/I= nodes with flexion deformity 1-5 degrees; I= nodes with flexion deformity 6-45 degrees; II= nodes with flexion deformity 46-90 degrees; III= nodes with flexion >90 degrees.

Abbreviations. Gy=gray; kV=kilovoltage; mA=milliamperes; mm=millimeter; NR=not reported; NSAID=non-steroidal anti-inflammatory drugs; RT=radiation therapy.

## APPENDIX J-3 DUPUYTREN’S CONTRACTURE QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall RoB
Betz, 2010, 20127225, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single group)^a^
Keilholz, 1996, 8960518, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single group)^a^
Latusek, 2017, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Unclear | NA | NA | No (Low concern) | High (Single group)^a^
Zirbs, 2015, 25201324, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single group)^a^
Adamietz-2001-11757183 Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern | Unclear | NA | NA | No (Low Concern) | High RoB (Single Group) ^a^

Notes.

a The study design is unable to estimate the effect of RT on outcomes.

Abbreviations. NA=not applicable.

## APPENDIX J-4 DUPUYTREN’S CONTRACTURE RESULTS SUMMARY

Author, Year, PMID | Treatment | Stage and Regression | Symptoms | QoL and Patient Satisfaction/ Experience of Care | Side Effects
Betz, 2010, 20127225 | Baseline vs follow-up; Follow-up, Median (range), y = 13 (NR) | Changes in stage, (N = 208), [median 13 y], N (%)^a,b^; Regression = 20 (9.6); Progression = 65 (31.3); Stable = 123 (59.1); Changes in stage by duration of disease (N = 208), [median 13 y], %^a^; Regression; 1-12 mo = 24; 13-24 mo = 11; 25-36 mo = 3; 37-48 mo = 3; > 48 mo = 3; Progression; 1-12 mo = 2; 13-24 mo = 19; 25-36 mo = 41; 37-48 mo = 43; > 48 mo = 55; Stable; 1-12 mo = 74; 13-24 mo = 70; 25-36 mo = 56; 37-48 mo = 53; > 48 mo = 41; Changes in stage by pre-RT stage, (N=208), [median 13 y], N (%)^a^; Regression; N = 7 (6); N/I = 10 (30); I = 3 (6); II, III and IV Zero cases; Progression in-field; N = 9 (8); N/I = 8 (24); I = 12 (24); II, III and IV Zero cases; Progression out-field; N = 0 (0); N/I = 2 (6); I = 4 (8); II, III and IV Zero cases; Progression in+out; N = 6 (5); N/I = 0 (0); I = 15 (30); II = 6 (86); III = 2 (100); IV = 1 (100); Stable; N 93 (81); N/I 13 (40); I 16 (32); II 1 (14); III and IV Zero cases; Change in numbers of nodules and cords (N = 208), [median 13 y], N (%)^c^; Regression = 50 (24); Progression in-field = 33 (16); Progression out-field = 21 (10); Progression in+out = 34 (16); Stable = 70 (34); Change in numbers of nodules and cords; By pre-RT stage (N=208), [median 13 y], N (%)^a,c^; Regression; N = 42 (37); N/I = 6 (18); I = 2 (4); II, III and IV Zero cases; Progression in-field; N = 17 (15); N/I = 5 (15); I = 11 (22); II, III and IV Zero cases; Progression out-field; N = 11 (10); N/I = 6 (18); I = 4 (8); II, III and IV Zero cases; Progression in+out; N = 9 (8); N/I = 0 (0); I = 15 (30); II = 7 (100); III = 2 (100); IV = 1 (100); Stable; N 36 (31); N/I 16 (48); I 18 (36); II, III, and IV Zero cases | Symptom relief (not defined) [median 13 y], N (%)^b^; Composite (Dysesthesia, Burning/itching, Pressure/tension) (N=87),; No Change = 12 (14); Minor relief = 28 (32); Good relief = 16 (18); Complete relief = 14 (16); Progression = 17 (20); Dysesthesia (N=8); No Change = 2 (25); Minor relief = 3 (37.5); Good relief = 1 (12.5); Complete relief = 0 (0); Progression = 2 (25); Pressure/tension (N=45); No Change = 6 (13.3); Minor relief = 13 (28.9); Good relief = 10 (22.2); Complete relief = 8 (17.8); Progression = 8 (17.8); Burning/itching (N=34); No Change = 4 (11.8); Minor relief = 12 (35.3); Good relief = 5 (14.7); Complete relief = 6 (17.6); Progression = 7 (20.6) | NR | Radiation Therapy Oncology Group/EORTC criteria.; Skin atrophy with occasional telangiectasia [median 13 y], N (%) = 14 (7); Dry skin and increased desquamation [median 13 y], N (%) = 47 (23); Erythema up to 1 y [median 13 y], N (%) = 5 (2); Chronic grade 3 or 4 reactions were not observed. No induction of cancer could be detected at last follow-up
Keilholz, 1996, 8960518 | Baseline vs follow-up; Follow-Up, Mean (range), y = 6 (1-12) | Change in stage (N = 142) [3 mo], N (%)^d^; No progression = 130 (92); Improvement = 10 (7); Decrease in functional status = 2 (1); Changes to size and consistency of palpable nodules and cords (N = 142) [3 mo], N (%)^e^; Stable = 33 (23); Moderate reduction =52 (37); Good reduction = 40 (28); Excellent reduction = 15 (11); Progression = 2 (1); Change in stage (N = 142) [mean follow-up of 6 +/− 2 y], N (%)^d^; Stable or improved = 133 (94); Progressions (in the RT field) = 9 (6); Changes to size and consistency of palpable nodules and cords (N = 142) [mean follow-up of 6 +/− 2 y] N (%); Stable = 24 (17%); Reduction of size and softer consistency = 102 (72%); Progression = 16 (11%); Change of palpable nodules and cords according to baseline stage [3 mo], N (%)^b,e^ Stage N (N=82); Stable = 17 (20.7); Moderate = 35 (42.7); Good = 23 (28.1); Excellent = 7 (8.5); Progression = 0 (0.0); Stage N/I (N=17); Stable = 2 (11.8); Moderate = 6 (35.3); Good = 7 (41.1); Excellent = 2 (11.8); Progression = 0 (0); Stage I (N=30); Stable = 6 (20.0); Moderate = 6 (20.0); Good = 10 (33.3); Excellent = 6 (20.0); Progression = 2 (6.7); Stage II/III (N=13); Stable = 8 (61.5); Moderate = 5 (38.5); Zero events on good and excellent. | Changes in complaints of symptoms (not defined) (N = 142) [3 mo], N (%); Unchanged = 25 (18); Moderate reduction = 64 (45); Major reduction = 41 (29); Complete relief = 6 (4); Worse symptoms = 6 (4) | Satisfaction of long-term outcome (time not specified) (N = 96), N (%) = 83 (87) | Total hands that developed acute mild skin reactions (Grade 1), erythema, and dry desquamation [time not specified] (N = 142), N (%) = 61 (43.0); Radiodermatitis with pronounced erythema and moderate edema (Grade 2); [time not specified] (N = 142), N (%) = 14 (10.0); Mild skin atrophy accompanied by slight fibrosis or occasional telangiectasia within the irradiated area [mean follow-up of 6 +/− 2 y], N (%) = 19 (13.0); Dry skin and desquamation within the irradiated area; [mean follow-up of 6 +/− 2 y], N (%) = 91 (64.0); Grade 3/4 toxicities were not observed.; Chronic Grade 3 or 4 reactions were not observed; During RT, most patients complained of itching and burning sensations.
Latusek, 2017 | Baseline vs follow-up; Follow-up, Mean, mo = 4.4^b^ | Change on condition after RT^f^; Immediately following RT; Improvement = 35%; Stable = 58%; Deterioration = 7%; At follow-up [mean 4.8mo]; Improvement = 57.5%; Stable = 35%; Deterioration = 7.5% | NR | NR | Erythema; [4.8mo] 7.5%; Superficial epidermal exfoliation; [4.8mo] 2.5%; Palmar dryness; [4.8mo] 2.5%
Zirbs, 2015, 25201324 | Baseline vs follow-up; Follow-up, Median (range), mo = 40 (6-115) | No further disease progression (including patients with regression); (not defined) (N = 206), [Median 40 mo], N (%) = 165 (80.0); Subjective therapeutic effect (reduction, not defined) (N = 426 nodes and cords), [Median 40 mo], N (%) = 92 (21.6) | Regression of symptoms (not defined) (N = 206),; [Median 40 mo], N (%) = 93 (45.0) | Patient’s satisfaction (VAS 0-10) (N =198); [Median 40 mo], Mean (SD) = 7.9 (2.7) | Side effects (N =206), [Time not specified], N (%); Erythema = 42 (20.4); Missing data = 27 (13.1); Dry skin = 82 (39.8); Missing data = 15 (7.3); Desquamation = 8 (3.8); Chronic Side-Effects (N=206), [>4 week], N (%); Desquamation = 8 (3.8); Skin atrophy = 7 (3.0); Lack of sweating = 8 (4.0); Telangiectasia = 6 (3.0); Sensory affection = 4 (2.0); Desquamation = 5 (2); Dry skin = 41 (20)
Adamietz-2001-11757183 | Baseline vs follow-up; Follow-up, Median (range), yrs = 10 (7–18) | Regression (N = 176 hands) [10 yrs], N (%); 18 (10%); Regression by lesion stage at baseline (Tubiana et al. classification) [10 yrs], N (%); 0 (N = 5) = 0 (0); N (N = 76) = 12 (16); N/I (N = 15) = 2 (13); I (N = 65) = 4 (6); II (N = 12) = 0 (0.0); III (N = 3) = 0 (0.0); Stable (N = 176 hands) [10 yrs], N (%); 86 (49); Stability by lesion stage at baseline (Tubiana et al. classification) [10 yrs], N (%) 0 (N = 5) = 5 (100); N (N = 76) = 52 (68); N/I (N = 15) = 8 (54); I (N = 65) = 19 (29); II (N = 12) = 2 (17); III (N = 3) = 0 (0.0); Progression in the field (N = 176 hands) [10 yrs], N (%); 38 (22); Progression in the field by lesion stage at baseline (Tubiana et al. classification) [10 yrs], N (%); 0 (N = 5) = 0 (0.0); N (N = 76) = 6 (8); N/I (N = 15) = 2 (13); I (N = 65) = 19 (29); II (N = 12) = 8 (66); III (N = 3) = 3 (100); Progression outside the field (N = 176 hands) [10 yrs], N (%); 34 (19); Progression outside the field by lesion stage at baseline (Tubiana et al. classification) [10 yrs], N (%); 0 (N = 5) = 0 (0.0); N (N = 76) = 6 (8); N/I (N = 15) = 3 (20); I (N = 65) = 23 (36); II (N = 12) = 2 (17); III (N = 3) = 0 (0.0); Recurrence in the former radiation field (N = 176 hands) [10 yrs], N (%); 38 (22) | NR | NR | Skin atrophy (occasionally associated with telangiectasia) (N = 176 hands) [10 yrs], N (%); 15 (8.5); Anhidrosis with severe scaling (N = 176 hands) [10 yrs], N (%); 44 (25); Side effects by LENT-SOMA score (min: 0.7, max: 3.5) (N = 176 hands) [10 yrs], N (%); Score 0.07 = 111 (63); Score 0.14 = 32 (18); Score 0.21 = 11(6); Score 0.28 = 4 (2.27); No late side effect (N = 176 hands) [10 yrs], N (%); 111 (63)

Notes.

a Staging followed Tubiana et al, which classification is based on the total flexion deformity/extension deficit of the involved the medial phalangeal and the proximal interphalangeal finger joints. Stage I = nodules, cords, skin retraction/fixation, no extension deficit/flexion deformity; Stage N/I = flexion deformity between 1 and 5 degrees; Stage I = 6-45 degrees; Stage II = 46-90 degrees; Stage III = 91-135 degrees; Stage IV = >135 degrees;

b Values calculated by the research team based on data provided in the article;

C Regression = Decrease in nodules/cord; Progression = Increase in nodules/cords; Stable = No change in nodules/cords;

d Staging according to Tubiana et al. which classification is based on the total flexion deformity/extension deficit of the involved the medial phalangeal and the proximal interphalangeal finger joints. Stage 0 = no (apparent) lesion; Stage N = nodule without flexion deformity; Stage N/I = flexion deformity between 1 and 5 degrees; Stage I = 6-45 degrees; Stage II = 46-90 degrees; Stage III = 91-135 degrees; Stage IV = >135 degrees;

e Stable = No change in of the flexion deformity; Moderate = 25-50% reduction of module or cord with some softening; Good = 51-75% reduction of module or cord with major softening; Excellent = >75% reduction of module or cord or complete resolution; Progression = progression of deformity or enlargement of area;

f Improvement was defined as a decrease in the size of nodules, reduction of contracture, or the improvement of manual function.

Abbreviations. EORTC=European Organization for Research and Treatment of Cancer mo=months; NR=not reported; QoL=quality of life; RT=radiation therapy; VAS=visual analogue scale; y=years.