# APPENDIX I PEYRONIE’S DISEASE

## APPENDIX I-1 PEYRONIE’S DISEASE DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Incrocci, 2000, 11113753, Netherlands | Single group | 1982-1997 | Other/Unclear | Primary treatment / prevention of recurrence | Patients with PD treated with RT | NR
Niewald, 2006, 16169684, Germany | Single group | 1983-2000 | Teaching Hospital | Primary treatment / prevention of recurrence | Patients with PD who were irradiated and had at least one complete follow-up data set | NR
Pietsch, 2018, 30370354, Germany | Single group | 1999-2008 | Other/Unclear | Primary treatment / prevention of recurrence | Patients with PD treated with superficial x-ray therapy | NR
Pambor, 2003, 14605750, Germany | Single group | [NR 7 year span] | Teaching Hospital, Single center | Primary treatment / prevention of recurrence | Patients with PD treated with superficial beta radiation therapy | NR
Meineke, 2003, 12627261 Germany | Single group | 1990-1995 | Technical University of Munich (polyclinic) | Primary treatment / prevention of recurrence | Patients with induration penis plastica (IPP) or the so-called Morbus Pyronine | NR

Abbreviations. NR: not reported; PD=Peyronie’s disease; PMID=PubMed ID; RT=Radiation therapy.

## APPENDIX I-2 PEYRONIE’S DISEASE BASELINE DATA

Author, Year, PMID | N Patients | Intervention | N Lesions | Age Mean (Range) | N (%) Male | N (%) White | Location | Lesion Age | Etiology | Size (mm) | Previous Treatment | Other
Incrocci, 2000, 11113753 | RT= 106 | Patients treated with either 9 fractions of 1.5 Gy (three fractions weekly, total dose=13.5Gy) using orthovoltage x-ray (N=64) or 6 fractions of 2 Gy (daily, total dose=12 Gy) with electrons (N=42) | NR | 59 (35-84) | 106 (100) | NR | Penis | Duration of symptoms before RT (months): median=6; mean=11; SD=NR; range=1-72 | Trauma to the penis = 19% | NR | Previously treated unsuccessfully = 22%; (Vitamin E = 5; Corticosteroids = 10; Verapamil = 1; Surgical correction of the penile deformity = 6; Not reported = 84) | Dupuytren’s disease=36%; Patients taking medication known to possibly affect sexual functioning (antihypertensive or antidepressant agents) (N = 106), N (%)^a^; At the time of RT = 31 (29); At follow-up = 56 (53)
Niewald, 2006, 16169684 | RT= 101 | Daily reactions of 2Gy delivered to total doses:; 30 Gy in 72 patients;; 36 Gy in 25 patients;; 32–34 Gy in 1 patient;; 38–40 Gy in 3 patients; Used Co-60 gamma rays or 4-MV, 6-MV photon beams of a linear accelerator, or a direct electron beam (5 MeV up to 8 MeV) depending on the location of the foci. | Number of foci (N=83), N(%): 1=54 (65); 2=25 (30); 3 or more=4 (5) | 54 (32-73) | 101 (100) | NR | Penis | Duration of symptoms before RT (months) (N = 80), Mean, (range) = 18 (1-204) | NR | Maximum diameter of foci (N-84), N (%):; <5mm = 7 (8);; 5-10mm = 36 (43);; >10mm = 41 (49) | Pretreatment (N=94), N(%)^a^:; Oral medication=24 (25.5);; Injections into the foci=10 (10.6);; Previous operation=2 (2.1);; Previous local RT before=1(1.1); No pretreatment=57 (60.6) | Dupuytren’s disease (N=88), N (%) = 15 (17.1); Symptoms progression before RT (N=69 patients), N(%) = 59 (85.5); Quality of foci (N=89), N(%): Fibrous = 28 (31); Cartilaginous=27 (30); Calcified=34 (39)
Pietsch, 2018, 30370354 | RT = 83 | 4 cycles of 50 kV photons at 25 mA with a 2 mm cellon filter and a 1 mm aluminum filter administered with superficial x-rays followed by a single dose of 4Gy two days in a row, for a total dose of 32 Gy | NR | 59 (8.3) (Mean, SD) | 83 (100) | NR | Penis | Duration of symptoms before RT (months):; Mean = 10.6; SD = 9.3; Median = 8 | NR | NR | NR | Progression type of PD^b^, N (%):; Very rapid = 24 (28.9);; Rapid = 33 (39.7);; Slow progression = 18 (21.7);; Batch-wise progression = 1 (1.2);; No answer = 7 (8.4); Cooccurring benign fibroproliferative disorders (N=83), N(%) = 28 (33.7%); Specific cooccurring disorder in those with cooccurring with benign fibroproliferative disorders (N=28), N (%):; Dupuytren’s disease = 22 (78.6); Plantar fibromatosis (Ledderhose Disease) = 5 (17.9); Knuckle pads = 4 (14.3); Keloids = 2 (7.1); Double affection in patients = 5 (17.9)
Pambor, 2003, 14605750 | RT = 58 | RT with beta radiation (6-8 MeV), 2 or 3 times a week 3Gy each time for a total of 24-30Gy | 58 | Median (IQR) 54 (34 - 67) | 15 (100) | NR | Penis, dorsal | Duration of symptoms (months), N (%):; <6 = 18 (31.0);; >6 = 15 (25.9);; Unclear = 25(43.1)] | NR | NR | 15 patients (26%) have history of failed conservative treatment (potassium para-aminobenzoate, Vitamin E, and/or hyaluronate) | Dupuytren’s disease, N (%) = 11 (19)
Meineke, 2003, 12627261 | RT = 67 | External beam: Total dose, 32 Gy, through10 fractions, 2-4 Gy per dose, 8-16 based on fraction dose over 420 days, using the Dermopan II (Siemens, Munich, Germany), 50 kV, 1.0 mm aluminum filter. | 76 | Age up to 29 yrs 2 (3.0); >29 to 39 yrs 4 (6.0); >39 to 49 yrs 10 (14.9); >49 to 59 yrs 30 (44.8); >59 to 69 yrs 16 (23.9); >69 to 79 yrs 5 (7.5) | 67 (100) | NR | Sagittal plane (N = 76 lesions):; Anterior third 19 (25); Middle third 31 (40.79); Posterior third 17 (22.37); Over the whole Length 2 (2.63); Frontal plane:; Dorsal 39 (51.32); Left 18 (23.68); Right 9 (11.84); Caudal 2 (2.63) | NR | Comorbidities (N = 67 patients):; Dupuytren’s disease = 21 (31.34); Knuckle pads = 6 (9.0); Ledderhose disease = 3 (4.5); Diabetes mellitus = 7 (10.4) | Size (N = 67 lesions); ≤ 1 ×1cm = 34 (44.74); Up to 2× 2 cm = 25 (32.89); Up to 2 ×4 cm =5 (6.58); ≥ 2× 4cm = 2 (2.63); No information = 10 (13.16) | NR | NR

Notes.

a Numbers estimated by research team based on percentages presented in the article;

b Very rapid = Weeks until 6 months; Rapid = Over 6 months until a year; Slow progression = In years.

Abbreviations. cm=centimeter; Gy=gray; kV=kilovoltage; mA=milliamperes; MeV=megavoltage; mm=millimeter; NR=not reported; PD=Peyronie’s disease; RT=radiation therapy; SD=standard deviation.

## APPENDIX I-3 PEYRONIE’S DISEASE QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat-analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representative ness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall RoB
Incrocci, 2000, 11113753, Single group | NA | NA | NA | Unclear | Yes (High concern)^a^ | NA | NA | No (High concern)^b^ | Yes (Low concern) | Yes (Low concern | Yes (Low concern | Yes (Low concern | NA | No (High concern)^c^ | No (Low concern) | High (Single group)^d^
Niewald, 2006, 16169684, Single group | NA | NA | NA | Unclear | Yes (High concern)^e^ | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern | Yes (Low concern | Yes (Low concern | NA | No (High concern)^c^ | No (Low concern) | High (Single group)^d^
Pietsch, 2018, 30370354, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern | No (High concern)^f^ | Yes (Low concern | NA | No (High concern)^c^ | No (Low concern) | High (Single group)^d^
Pambor, 2003, 14605750 | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low Concern) | Yes (Low concern) | Yes (Low concern) | No (High concern)^g^ | Unclear | NA | No (High concern)^c^ | No (Low concern) | High RoB (Single group)^d^
Meineke, 2003, 12627261 | NA | NA | NA | Unclear | No (Low concern) | NA | MA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern | Unclear | NA | NA | No (Low concern) | High RoB (Single group)^d^

Notes.

a 179 patients treated with RT but only 130 could be sent a questionnaire, and only 106 responded to the questionnaire;

b Follow-up time unclear;

c Crude analysis;

d The study design is unable to estimate the effect of RT on outcomes;

e 40% missing at last follow-up time point (1400 days);

f Symptoms not clearly defined;

g Methods for outcome assessment was not clear.

Abbreviations. NA=not applicable.

## APPENDIX I-4 PEYRONIE’S DISEASE RESULTS SUMMARY

Author, Year, PMID | Comparator | Efficacy Mean (SD) or N (%) | Side Effects N (%) | Patient Satisfaction/Experience/QoL Mean (SD) or N (%)
Incrocci, 2000, 11113753 | RT 12 or 13.5 Gy; Baseline vs follow-up (RT between 1982-1997 and follow-up questionnaire conducted in 1998); Follow-up = unknown | Patients reporting diminished pain (not defined) at follow-up of the 47 (44%) who had reported pain before RT, N (%)^a^ = 33 (69); Patients with pain before RT compared to patients with diminished pain after RT (N=106); RD (95% CI)^a^ = −0.132 (−0.261, −0.003) p=0.045; Patients reporting decreased penile curvature (not defined) at follow-up of the 103 (97%) who had reported curvature before RT, N (%)^a^ = 30 (29); RD (95% CI)^a^ = 0.689 (0.587, 0.780) p<0.001; Patients reporting improved erectile disfunction (not defined) at follow-up of the 22 (21%) reporting erectile disfunction before RT, N (%)^a^ = 3 (13); RD (95% CI)^a^ = 0.179 (0.096, 0.263) p<0.001; Patients reporting being sexually active (not defined) (N=106), N (%)^a^; Before RT = 98 (92); After RT = 76 (72); p = 0.002; RD (95% CI)^a^ = 0.208 (0.108, 0.307); Patients who reported no decrease in sexual interest after RT (N=106), N (%)^a^ = 66 (62); Patients who reported no decrease in sexual activity after RT, N (%)^a^ = 35 (33); Patients who reported no decrease in sexual pleasure after RT, N (%)^a^ = 54 (51); Frequency of spontaneous erections in the past 4 weeks (N=91), N(%); Never = 33 (36); 1/wk = 25 (27); 2-6/wk = 19 (21); 1/day = 10 (11); ≥2/day = 4 (5); Patients reporting difficulty getting an erection in the past 4 weeks (N=67), N (%); No = 33 (49); Sometimes = 21 (31); Always = 13 (20); Patients reporting difficulty maintaining an erection in the past 4 weeks (N=67), N (%); No = 26 (39); Sometimes = 26 (39); Always = 15 (22); Rigidity of spontaneous erections in the past 4 weeks (N=59), N (%); Not at all = 1 (2); Somewhat = 5 (8); Half = 26 (44); Rigid = 20 (34); Very Rigid = 7 (12); Rigidity of erections during sexual activity in the past 4 weeks (N=68), N (%); Not at all = 3 (4); Somewhat = 0 (0); Half = 34 (50); Rigid = 18 (27); Very Rigid = 13 (19); Patients who underwent surgery to correct persisting penile curvature after RT, N(%)^a^ = 25 (24); At the time of the questionnaire (before Viagra was introduced in The Netherlands), only 13 patients were receiving ED treatment: 5 received intracavernosal injections, 3 used a vacuum device, and in 5 patients the treatment was not specified | Discomfort during RT (N=106), N (%)^a^ = 12 (11) | Satisfaction with current (past 4 weeks) sexual life after RT (N=106), N (%)^a^; Not satisfied = 52 (49); Somewhat satisfied = 27 (25); Very much satisfied = 28 (26)
Niewald, 2006, 16169684 | RT 30-40 Gy; Baseline vs follow-up (best result from any timepoint or at 80, 460, 1100, 1400 days); Follow-up= 80-1400 days | Pain (undefined), Numerator/Denominator (%):; Before RT = 48/92 (52); 80 days = 26/87 (30); 460 days = 25/92 (27); 1100 days = 14/69 (20); 1400 days = 5/56 (10); Before RT vs 1400 days, RD (95% CI) = 0.43 (0.31, 0.56), p<0.001^a^; Deviation (undefined), N (%); Individual best at any timepoint (N=101):; Improvement = 47 (47); No Change = 52 (51); Progression = 2 (2); At 80 days (N=101):; Improved = 23 (23); Stable = 71 (70); Worse = 7 (7); At 460 days (N=89):; Improved = 23 (26); Stable = 55 (62); Worse = 11 (12); At 1100 days (N=68):; Improved = 17 (25); Stable = 46 (68); Worse = 5 (7); At 1400 days (N=47):; Improved = 15 (32); Stable = 29 (62); Worse = 3 (6); Number of foci (undefined), N (%); Individual best at any timepoint (N=101):; Improvement = 32 (32); No Change = 69 (68); Progression = 0 (0); At 80 days (N=101):; Improved = 16 (16); Stable = 79 (78); Worse = 6 (6); At 460 days (N=87):; Improved = 16 (18); Stable = 66 (76); Worse = 5 (6); At 1100 days (N=62):; Improved = 9 (15); Stable = 52 (84); Worse = 1 (1); At 1400 days (N=36):; Improved = 5 (14); Stable = 30 (83); Worse = 1 (3); Size of foci (undefined), N (%); Individual best at any timepoint (N=101):; Improvement = 49 (49); No Change = 52 (51); Progression = 0 (0); At 80 days (N =101):; Improved = 23 (23); Stable = 71 (70); Worse = 7 (7); At 460 days (N=93):; Improved = 28 (30); Stable = 57 (61); Worse = 8 (9); At 1100 days (N=69):; Improved = 16 (23); Stable = 47 (68); Worse = 6 (9); At 1400 days (N=48):; Improved = 13 (27); Stable = 32 (67); Worse = 3 (6); Quality of foci (undefined), N (%); Individual best at any timepoint (N=101):; Improvement = 52 (51); No Change = 48 (48); Progression = 1 (1); At 80 days (N=101):; Improved = 32 (32); Stable = 65 (64); Worse = 4 (4); At 460 days (N=84):; Improved = 22 (26); Stable = 54 (64); Worse = 8 (10); At 1100 days (N=63):; Improved = 18 (29); Stable = 42 (67); Worse = 3 (4); At 1400 days (N=36):; Improved = 8 (22); Stable = 26 (72); Worse = 2 (6); Erectile dysfunction, Numerator/Denominator (%):; Before RT = 1/72 (1); 80 days = 6/85 (7); 460 days = 4/84 (5); 1100 days = 6/71 (8); 1400 days = 3/47 (6); Before RT vs 1400 days, RD (95% CI) = −0.05 (−0.12, 0.02), p=0.191^a^ | Acute dermatitis (Grade 1 Common Toxicity Criteria) at the end of RT (N=101), N (%) = 28 (28); Mild urethritis (Grade; 1 Common Toxicity Criteria) at the end of RT (N=101), N (%) = 4 (4); Long term side effects (note defined), N (%) = 0 (0); Indication of malignancy during follow-up (not defined), N (%) = 0 (0); Patients who received oral medication after RT (N=101), N (%) = 2 (2)
Pietsch, 2018, 30370354 | RT 32 Gy; Baseline to follow-up; Follow-up (mo):; Mean = 52; SD = 23; Media = 49; Range = 8-98 | Regression of symptoms (undefined) (N=83), N (%):; Yes = 39 (47); No = 39 (47); Unclear = 5 (6); Recurrence of symptoms (undefined (N = 83), N (%):; Yes = 1 (1.2); No = 75 (90.4); Unclear = 7 (8.4); Stopped PD progression (undefined) (N=83), N (%):; Yes = 65 (78.3); No = 12 (14.5); Unclear = 6 (7.2) | Side effects (N = 83), N (%):; Telangiectasias = 10 (12); Atrophic skin = 8 (9.6); Paresthesia = 5 (6); Erythema = 32 (38.6); Dry skin = 8 (9.6) | Subjective satisfaction using visual analog scale^b^ in 80/83 patients:; Mean (SD) = 6.2 (3.1); Median = 7; Positive impact on sexual life (N=83), N (%):; Yes = 30 (36.2); No = 44 (53); Unclear = 9 (10.8)
Pambor, 2003, 14605750 | RT 24 to 30 Gy; Follow- up = 6 weeks- 2 years | Complete resolution of all symptoms (cure) (N = 58), N(%); By 6 weeks = 1 (1.7); By 3 months = 2 (3.4); By ½ year = 3 (5.2); By 1 year = 5 (8.6); By 2 years = 6 (10.3); 50% Regression (Significant decrease in induration and symptoms) (N = 58), N (%); By 6 weeks = 1 (1.7); By 3 months = 3 (5.2); By ½ year = 5 (8.6); By 1 year = 8 (13.8%); By 2 years = 10 (17.2%); Improvement in penile induration after therapy vs before therapy among those with symptoms/signs at baseline (N = 58), N (%) = 16 (27.6); Improvement in Penile deviation on erection after therapy vs before therapy among those with symptoms/signs at baseline (N = 54), N (%): 13 (24.1); Improvement in pain on erection after therapy vs before therapy among those with symptoms/signs at baseline (N = 20), N (%): 13 (65) | No patient had telangiectasias, ulcers, or atrophy after treatment | ND
Meineke, 2003, 12627261 | RT = Up to 32 (Gy); Follow-up = 6mo-5yrs | Progression (N = 67) [6mo-5y], N (%); Could be stopped by therapy = 58 (86.6); Could not be stopped by therapy = 5 (7.5); No longer progressing (not fully defined) = 4 (6.0); Symptom Improvement (N=67) [6mo-5y], N (%); Reduction of all symptoms = 7 (10.7); Significant improvement of symptoms = 29 (43.3); Moderate to mild improvement of symptoms = 10 (14.9); Stable symptoms = 16 (23.9); Deterioration = 5 (7.5); Change in pain (of those reporting pain before RT) (N = 25) [6mo-5y], N (%); Complete regression = 17 (68.0); Stark Improvement = 4 (17.0); Medium/low improvement = 0 (0.0); Same = 2 (8.0); Increase = 2 (8.0); Induration changes (N = 70) [6mo-5y], N (%); Complete improvement = 23 (32.9); Some Regression (including strong, medium, little) = 11 (15.7); Softer = 7 (10); Same = 23 (32.9); Worse = 6 (8.9); Deviation changes (N = 58) [6mo-5y], N (%); Complete improvement = 7 (12.1); Some Improvement (including, strong, medium and little) = 16 (27.6); Same = 30 (51.7); Worse = 5 (8.7); Onset of improvement (Pain improvement), N (%); After the 1st radiation (N=21) = 3 (14.3); After several radiation treatments (N=21) = 8 (38.1); Onset of improvement (induration) (N=39) = NR; After several radiation treatments (N=39) = 12 (30.8); Onset of improvement (Deviation) (N=20), N (%); After the 1st radiation = NR; After several radiation treatments = 4 (20); Onset of improvement (Pain) In relation to therapy time, N (%); Toward the end of therapy (N=21) = 4 (19); ≤ 3 months after the end of therapy (N=20) = 3 (14.3); > 3 months after the end of therapy (N=20) = 3 (14.3); Onset of improvement (Induration) In relation to therapy time (N=39), N (%); Toward the end of therapy = 11 (28.2); ≤ 3 months after the end of therapy = 11(28.2); > 3 months after the end of therapy = 5 (12.8); Onset of improvement (Deviation) In relation to therapy time (N=20), N (%); Toward the end of therapy = 8 (40); ≤ 3 months after the end of therapy = 6 (30); > 3 months after the end of therapy = [underlined: 2](10) | Discrete telangiectasias and minimal hyperpigmentation (N=67) [6mo-5y], N (%); 6 (9); (a patient with a second cycle of radiation); Minor redness in radiation field (N=67) [6mo-5y], N (%); 2 (3)

Notes.

a Numbers estimated by research team based on percentages presented in the article;

b 1=not satisfied, 10=very satisfied.

Abbreviations. CI=confidence interval; Gy=gray; mo=months; PD=Peyronie’s disease; PMID=PubMed ID; QoL=quality of life; RD=risk difference; RT=radiation therapy; SD=standard deviation; wk=week; y=years.