# APPENDIX H OSTEOARTHRITIS

## APPENDIX H-1 OSTEOARTHRITIS DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Minten, 2016, 26747050; Netherlands | Systematic review | 1982-2013 (included studies) | NR | Treatment of OA | Studies aimed to treat OA, used an intervention of external beam radiotherapy, the effects of RT on pain or functioning were assessed, and study was a journal article. | No primary data presented, in a language other than English, German or Dutch, or published prior to 1980
Mahler, 2019 30366945 NTR4574; Netherlands^a^ | RCT | 2015-2017 | Teaching hospital Other/unclear | Primary treatment/prevention of recurrence | Patients from rheumatology outpatient clinic who fulfilled the clinical ACR knee OA criteria, were >= 50 years old, had a numeric pain score of >=5/10 in the index knee, and had insufficient response to analgesics and exercise therapy | Treatment by a physical therapist in the last 6 months, NRS pain score >2/10 in the contralateral knee or hips, corticosteroids int eh previous 4 weeks, fibromyalgia, Kellgren & Lawrence score >3
Minten 2018 30231990 NTR4574; Netherlands^a^ | RCT | 2016-2017 | Teaching hospital Other/unclear | Primary treatment/prevention of recurrence | ACR criteria hand OA, Age>=50, hand pain score >=5/10 on NRS for at least 15 days of the last 30 days despite analgesic use and occupational and/or physical therapy; ability to read, write, and communicate well in Dutch | Predominant pain in the metacarpophalangeal joins and or wrist; unilateral hand OA; treatment for hand OA by an occupational or physical therapist in the last 6 months; other rheumatic diseases with hand localization; previous or scheduled surgical treatment on hand joints; corticosteroid injections in the previous 4 weeks; fibromyalgia according to 2011 modified ACR criteria; presence of a pacemaker or implantable cardioverter-defibrillator; Kellgren & Lawrence score >3 in over 25% of the hand joints;
Niewald 2022 34724085 DKRS00011870; Germany | RCT (treated as two single arm studies) | | Teaching hospital | Primary treatment/prevention of recurrence | Clinical diagnosis of OA of the knee and/or hand or finger joints, radiological proof of the diagnosis (plain radiographs), duration of anamnesis more than 3 months, favorable general health status. | Patients presenting with previous joint replacement; previous radiation therapy to the affected joint; previous trauma; rheumatic, arterial, or venous vessel diseases; manifest lymphatic edema; pregnancy or breastfeeding; or severe psychiatric disorders. Patients having undergone surgical interventions or injections to the involved joint after radiotherapy were excluded as soon as this therapy became known.
Rühle 2021 34342662; Germany | Single group | 2008-2020 | Other/unclear | Primary treatment/prevention of recurrence | >= 65 years at the time of RT
Weissmann 2022 35046940; Germany | Single group | 2004-2019 | Teaching hospital | Primary treatment/prevention of recurrence

Notes.

a Copublication: Van den Ende, C.H., Minten, M.J., Leseman-Hoogenboom, M.M., van den Hoogen, F.H., Den Broeder, A.A., Mahler, E.A. and Poortmans, P.M., 2020. Long-term efficacy of low-dose radiation therapy on symptoms in patients with knee and hand osteoarthritis: Follow-up results of two parallel randomized, sham-controlled trials. The Lancet Rheumatology, 2(1), pp.e42–e49 38258275 .

Abbreviations. NR=not reported; OA=osteoarthritis; PMID=PubMed ID; RCT=randomized controlled trial; RT=radiation therapy.

## APPENDIX H-2 OSTEOARTHRITIS BASELINE DATA

Author, Year, PMID | N Patients | Intervention | N Lesions | Age (Years), Mean (SD) | N (%) Male | N (%) White | Location | Lesion Age | Previous Treatment, N (%) | Other
Minten, 2016, 26747050 | 2164 (OA patients) | 0.5-12 Gy | NR | Most between 50-70 | 28 (53%) | NR | Knee, Hip, Shoulder, Spine, Thumb | Duration of symptoms: <8 weeks- 15 years | NR | Varied
Mahler, 2019 30366945 | RT = 27 | Six fractions of 1 Gy delivered every other day over 2 weeks for a total dose of 6 Gy | NR | 65 (9) | 27 (49.1)^a^ | NR | Knee | Duration of symptoms ≤5 years (N=54), N (%): 30 (55.5)^a^ | Analgesic use in previous month: 35 (63.6)^a^ | Kellgren and Lawrence >=2, N (%) = 32 (58.2)^a^
Mahler, 2019 30366945 | Sham = 28 | The radiation therapy device was not activated, and patients were exposed to recordings of the sound of the device | NR | 65 (9) | 27 (49.1)^a^ | NR | Knee | Duration of symptoms ≤5 years (N=54), N (%): 30 (55.5)^a^ | Analgesic use in previous month: 35 (63.6)^a^ | Kellgren and Lawrence >=2, N (%) = 32 (58.2)^a^
Minten, 2018 30231990 | RT = 28 | Six fractions of 1 Gy, delivered every other day over 2 weeks, for a total dose of 6 Gy | NR | 65 (7) | 12 (21.4)^a^ | NR | Hand | Duration of symptoms ≥ 5 years, N (%): 34 (60.7)^a^ | Medication use, yes: 43 (76.8)^a^ | RT arm Kellgren and Lawrence >=2 joint count, n (0-30), median (IQR): 10.5 (6.5- 13.5); Sham Arm Kellgren and Lawrence >=2 joint count, n (0-30), median (IQR): 6 (2-8.5)
Minten, 2018 30231990 | Sham = 28 | Sham: Received six 0 Gy-fractions over the two-week period, during which an audio sound were played to mimic sounds of a linear accelerator during operation | NR | 65 (7) | 12 (21.4)^a^ | NR | Hand | Duration of symptoms ≥ 5 years, N (%): 34 (60.7)^a^ | Medication use, yes: 43 (76.8)^a^ | RT arm Kellgren and Lawrence >=2 joint count, n (0-30), median (IQR): 10.5 (6.5- 13.5); Sham Arm Kellgren and Lawrence >=2 joint count, n (0-30), median (IQR): 6 (2-8.5)
Niewald 2022 34724085 | RT (Standard Dose) = NR^b^ | Received 6 fractions of 0.5 Gy twice a week for a total dose of 3.0 Gy | 110 | 68.2 (NR) | NR | NR | Location, N(%):; Hand =77 (70); Knee =33 (30); Bilateral =39 (62); Unilateral =24 (38) | Duration of pain (months), M (SD) = 56.2 (52.3) | Previous treatment, N (%):; Ice/heat =52 (47);; Ultrasound =0;; Microwaves =2 (2);; Oral medication = 77 (70);; Injections =34 (31);; External splints =4 (4);; Arthroscopy (multiple choices possible) =16 (15)
Niewald 2022 34724085 | RT (Experimental Dose) = NR^b^ | Received 6 fractions of 0.05 Gy twice a week for a total dose of 0.3 Gy | 111 | 66.3 (NR) | NR | NR | Location, N(%):; Hand = 81 (73); Knee = 30 (27); Bilateral = 45 (61); Unilateral = 29 (39) | Duration of pain (months), M(SD) = 49.6 (46) | Previous treatment, N(%):; Ice/heat = 33 (30);; Ultrasound = 0;; Microwaves = 2 (2);; Oral medication = 69 (62);; Injections = 24 (22);; External splints = 2 (2);; Arthroscopy (multiple choices possible) = 12 (11)
Rühle 2021 34342662 | RT = 970 | 6 fractions of 0.5 or 1 Gy doses given two or three times a week (total dose of 3-6 Gy) via a linear accelerator either after computed tomography-based 3-dimensional treatment planning or after treatment simulation using 2-dimensional X-ray imaging. | 1185 | 76 (65-98); Median (Range); Mean (SD) = 76 (5.5)^a^ | 327 (27.6)^a^ of lesions | NR | Location, N (%):; Hand = 363 (30.6);; Shoulder = 147 (12.4);; Hip =33 (2.8);; Knee = 419 (35.4);; Foot = 219 (18.5);; Others =4 (0.3) | NR | NSAIDs = 733 (61.9); Intraarticular corticosteroid injection = 221 (18.6)
Weissmann 2022 35046940 | RT = 196 | 6 fractions of 0.5 or 1 Gy doses (total dose of 3-6 Gy) delivered over 3 weeks with an interfractional radiation-free interval of at least 2 days. | NR | 65.9 (14.5) | 47 (24)^a^ | NR | Location, N (%):; Foot and ankle; Right = 83 (42); Left = 73 (37);; Both = 40 (20) | NR | All patients had received several therapies before undergoing LDRT

Notes.

a Values calculated by the research team based on data provided in the article;

b Total patients for each arm not reported, but there were 133 total in both the standard and experimental dose arms.

Abbreviations. Gy=gray; IQR=interquartile range; LDRT=low-dose radiation therapy; NR=not reported; NSAIDs=non-steroidal anti-inflammatories; OA=osteoarthritis; PMID=PubMed ID; RT=radiation therapy; SD=standard deviation. (https://www.bing.com/ck/a?!&&p=51be4dc053c7bedeJmltdHM9MTY5MjgzNTIwMCZpZ3VpZD0yYWFhMmE0OC1mYzIzLTY5NDctMTE2NS0zOTc4ZmRiMDY4YjAmaW5zaWQ9NjA2OA&ptn=3&hsh=3&fclid=2aaa2a48-fc23-6947-1165-3978fdb068b0&psq=nsaids&u=a1aHR0cHM6Ly9lbi53aWtpcGVkaWEub3JnL3dpa2kvTm9uc3Rlcm9pZGFsX2FudGktaW5mbGFtbWF0b3J5X2RydWc&ntb=1)

## APPENDIX H-3 OSTEOARTHRITIS SYSTEMATIC REVIEW QUALITY RATING (AMSTAR-2)

Author, Year, PMID, Design | Did the research questions and inclusion criteria for the review include the components of PICO? | Did the report of the review contain an explicit statement that the review methods were established prior to the conduct of the review and did the report justify any significant deviations from the protocol? | Did the review authors explain their selection of the study designs for inclusion in the review? | Did the review authors use a comprehensive literature search strategy? | Did the review authors perform study selection in duplicate? | Did the review authors perform data extraction in duplicate? | Did the review authors provide a list of excluded studies and justify the exclusions? | Did the review authors describe the included studies in adequate detail? | Did the review authors use a satisfactory technique for assessing the risk of bias (RoB) in individual studies that were included in the review? | Did the review authors report on the sources of funding for the studies included in the review? | If meta-analysis was performed did the review authors use appropriate methods for statistical combination of results? | If meta-analysis was performed, did the review authors assess the potential impact of RoB in individual studies on the results of the meta-analysis or other evidence synthesis? | Did the review authors account for RoB in individual studies when interpreting/ discussing the results of the review? | Did the review authors provide a satisfactory explanation for, and discussion of, any heterogeneity observed in the results of the review? | If they performed quantitative synthesis did the review authors carry out an adequate investigation of publication bias (small study bias) and discuss its likely impact on the results of the review? | Did the review authors report any potential sources of conflict of interest, including any funding they received for conducting the review? | Overall
Minten, 2016, 2674705 0SR | No (High concern)^a^ | Partial Yes (Moderate concern)^b^ | No (High concern)^c^ | Partial Yes (Moderate concern)^d^ | Yes (Low concern) | No (High concern)^e^ | Partial Yes (Moderate concern)^f^ | Partial Yes (Moderate concern)^g^ | Yes (Low concern) | No (High concern)^h^ | NA | NA | Yes (low concern) | No (High concern)^i^ | NA | Yes (low concern) | Medium

Notes.

a Population and outcomes not specified;

b Indicated that PRISMA guidelines were followed but was not explicit about when review methods were established;

c No statement about why they chose to include noncomparative studies, though this was likely due to literature availability;

d Did not appear to review trial/study registries or grey literature;

e No statement about extraction preformed in duplicate;

f Provided justification for some of the excluded studies but did not provide a list of excluded studies;

g Study settings were not described;

h Did not report funding sources of the included studies;

I No discussion of heterogeneity.

Abbreviations. NA=not applicable; PMID: PubMed ID; SR=systematic review.

## APPENDIX H-4 OSTEOARTHRITIS QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat-analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall EOB
Mahler, 2019, 30366945, RCT | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Low (RCT)
Minten, 2018, 30231990, RCT | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Low (RCT)
Niewald 2022, 34724085, RCT – Single group | NA | NA | NA | Unclear | Yes (High concern)^a^ | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (RCT-Assessed as single group)
Rühle 2021, 34342662, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | No (High concern)^b^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single group)^c^
Weissmann 2022, 35046940, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single group)^c^

Notes.

a Seven in standard group lost to follow-up; 1 in the experimental group lost to follow-up;

b Results in figures are not all reported in the text;

c The study design is unable to estimate the effect of RT on outcomes.

Abbreviations. NA=not applicable; RCT=randomized controlled trial.

## APPENDIX H-5 OSTEOARTHRITIS RESULTS SUMMARY

Author, Year, PMID | Comparator | Efficacy | Side Effects | Patient Satisfaction/Experience/QoL
Minten, 2016, 26747050 | All included studies were single group | Insufficient evidence for a positive effect of [RT] on pain; Insufficient evidence for a positive effect of [RT] on functioning | Insufficient evidence for the safety of [RT] as treatment for OA. | NR
Mahler, 2019^a^ 30366945 | RT 6 Gy vs Sham; Follow-up, mo= 1, 2, and 3 | Pain (WOMAC), M (SD); Baseline (N = 27 vs 28):; 59 (14) vs 61 (17); Absolute change at 3-month follow-up (N = 27 vs 28):; 8 (3) vs 11 (14); β (95% CI) = −3 (−10,4)^b^; Mean difference (95% CI) from baseline to 12 mo:; −1.9 (−9.9, 6.0)^c^; Pain (NRS)^d^, M (SD); Baseline (N = 27 vs 28):; 5.8 (1.6) vs 5.4 (1.6); Absolute change at 3-month follow-up (N = 27 vs 28):; −1.1 (1.6) vs −1.3 (2.4); RT vs Sham, β (95% CI) = 0.1 (−0.9, 1.2)^b^; Function (WOMAC), M (SD); Baseline (N = 27 vs 28):; 60 (17) vs 62 (19); Absolute change at 3-month follow-up (N = 26 vs 28):; 9.7 (8) vs 6.3 (14); β (95% CI) = 4 (−3, 10)^b^; Mean difference (95% CI) from baseline to 12 mo:; −1.0 (9.0, 6.6)^c^; PGA of knee OA impact during the previous week, M (SD); Baseline (N = 27 vs 28):; 5.6 (2.2) vs 4.6 (2.3); Absolute change at 3-month follow-up (N = 27 vs 28):; −1.0 (2) vs −0.9 (3); β (95% CI) = 0 (−1, 1)^b^; Mean difference (95% CI) from baseline to 12 mo:; 0.0 (−1.2, 1.2)^c^; Stiffness (WOMAC), M (SD); Baseline (N = 27 vs 28):; 47 (13) vs 55 (20); Absolute change at 3-month follow-up (N = 27 vs 28):; −11 (9) vs 9 (21); β (95% CI) = 2 (−8, 13)^b^; Proportion OMERACT-OARSI responders, % (95% CI)^f^; 1 month follow-up (N = 27 vs 28):; 37 (19, 55) vs 21 (6, 37); Difference in proportion, % (95% CI) = 16 (−8, 39); OR =2.3 (0.7, 7.5)^b^; 2 months follow-up (N = 27 vs 28):; 33 (16, 51) vs 22 (9, 42); Difference in proportion, % (95% CI) = 11 (−13, 35); OR = 1.8 (0.5, 6.3)^b^; 3 months follow-up (N = 27 vs 28):; 44 (26, 63) vs 43 (25, 61); Difference in proportion, % (95% CI) = 2 (−25, 28); p =0.9; OR = 1.1 (0.4, 3.2)^b^; OR =1.3 (0.4, 4.2)^g^; 12 months follow-up (N =25 vs 25), N (%):; 13 (52) vs 11 (44); Difference in proportion, % (95% CI) = 8 (−29, 35); OR = 1.41 (0.45, 4.48)^b^ | Severe knee pain during and after treatment (N = 27 vs 28), N (%); 0 (0) vs 1 (4)^e^; Cold sensation in lower leg (N = 27 vs 28), N (%); 0 (0) vs 1 (4)^e^; Severe back pain after fall at home, leading to discontinuation of treatment (N = 27 vs 28), N (%); 1 (4) vs 0 (0); Colon carcinoma diagnosis, (N = 27 vs 28), N (%); 0 (0) vs 2 (7)^e^; Fatigue (N = 27 vs 28), N (%); 6 (22) vs 3 (11); Local reactions were comparable between groups; Side effects between baseline to 12 mo (N =27 vs 28), N (%); Skin reactions = 5 (19) vs 5 (18); Nail reactions = 4 (15) vs 3 (11); Fatigue = 6 (22) vs 4 (14); Other reactions = 3 (11) vs 4 (14); Any reactions = 10 (37) vs 10 (36); Serious adverse events = 0 (0) vs 3 (11) | SF36 Mental Component Scale; M (SD); Baseline (N = 25 vs 28):; 53 (10) vs 52 (10); Absolute change at 3-mo follow-up (N = 25 vs 27):; 0.9 (8.4) vs −4.2 (10); β (95% CI) = 5 (0,10)^b^; SF36 Physical Component Scale, M (SD); Baseline (N = 27 vs 28):; 39 (7) vs 39 (8); Absolute change at 3-month follow-up (N = 25 vs 27):; 0.1 (7.0) vs 2.4 (6.9); β (95% CI) = −2 (−6, 2)^b^
Minten 2018 30231990^a^ | RT 6 Gy vs Sham; Follow-up, mo = 1, 2, and 3 | Pain (AUSCAN) (N = 28 vs 28), M (SD); Baseline; 54 (19) vs 56 (15); Absolute change, 3-month follow-up:; −3.3 (12) vs −7.8 (16); β (95% CI) = 4.5 (−3.4,12)^b^; MD (95% CI) from baseline to 12 mo:; 3.3 (−4.6, 11.2)^c^; Pain (NRS)^d^ (N = 28 vs 28), M (SD); Baseline; 6.1 (1.9) vs 6.3 (1.5); Absolute change, 3-month follow-up:; −1.1 (1.6) vs −0.9 (2.3); β (95% CI) = −0.1 (−1.2, 1.0)^b^; Function (AUSCAN) (N = 28 vs 28), M (SD); Baseline; 55 (25) vs 59 (16); Absolute change, 3-month follow-up:; −2.6 (12) vs −9.9 (17); β (95% CI) = 7.4 (−0.8, 16)^b^; Mean difference (95% CI) from baseline to 12 mo:; −1.2 (−8.3, 5.8)^c^; PGA (N = 28 vs 28), M (SD); Baseline; 5.3 (2.2) vs 5.9 (1.7); Absolute change, 3-month follow-up:; −0.8 (2.3) vs −1.1 (2.3); β (95% CI) = 0.4 (−0.9, 1.6)^b^; Mean difference (95% CI) from baseline to 12 mo:; −0.1 (−1.2, 1.1)^c^; Stiffness (AUSCAN) (N = 28 vs 28), M (SD); Baseline; 56 (24) vs 62 (20); Absolute change, 3-month follow-up:; −1.4 (17) vs −7.6 (21); β (95% CI) = 6.0 (−4.5, 17)^b^; Proportion OMERACT-OARSI responders (N = 28 vs 28), N (%)^h^; 1 month follow-up:; 5 (18) vs 7 (25); Difference in proportion, % (95% CI) = −7 (−29, −14); OR (95% CI) = 0.65 (0.18, 2.35)^b^; 2-month follow-up:; 8 (29) vs 9 (32); Difference in proportion, % (95% CI) = −4 (−28, 20); OR (95% CI) = 0.82 (0.26, 2.60)^b^; 3-month follow-up:; 8 (29) vs 10 (36); Difference in proportion, % (95% CI) = −7 (−31,17); OR (95% CI) = 0.69 (0.22, 2.17)^b^; 12 months follow-up (N =26 vs 26), N (%):; 8 (31) vs 7 (26); Difference in proportion, % (95% CI) = 4 (−20, 29); OR = 1.23 (0.37, 4.12)^b^ | Skin reaction (undefined) (N = 28 vs 28), 3-month follow-up, N (%); 13 (46.4) vs 11 (39.3)^e^; Nail reaction (undefined) (N = 28 vs 28), 3-month follow-up, N (%); 8 (28.6) vs 3 (10.7)^e^; Fatigue (undefined) (N = 28 vs 28), 3-month follow-up, N (%); 7 (25.0) vs 6 (21.4)^e^; Other reactions (undefined) (N = 28 vs 28), 3-month follow-up, N (%); 9 (32.1) vs 6 (21.4)^e^; Serious adverse events (undefined) (N = 28 vs 28), 3-month follow-up, N (%); 2 (7.1) vs 0 (0); Withdrawal due to AE (nail discoloration) (N = 28 vs 28), N (%); 1 (4) vs 0 (0); Side effects between baseline to 12 mo (N = 28 vs 28), N (%); Skin reactions = 14 (50) vs 12 (43); Nail reactions = 10 (36) vs 4 (14); Fatigue = 8 (29) vs 8 (29); Other reactions = 9 (32) vs 6 (21); Any reactions = 21 (75) vs 18 (64); Serious adverse events = 2 (7) vs 0 (0) | SF36 Mental Component Scale (N = 28 vs 28), M (SD); Baseline; 55 (9) vs 50 (11); Absolute change, 3-month follow-up:; 1.6 (6.9) vs 1.0 (8.9); β (95% CI) = 0.6 (−3.9, 5.0)^b^; Between group difference at 3-month (95% CI) = 5.7 (0.6, 10.1); SF36 Physical Component Scale (N = 28 vs 28), M (SD); Baseline; 38 (9) vs 36 (8); Absolute change, 3-month follow-up:; 1.4 (6.8) vs 2.3 (6.0); β (95% CI) = −1.1 (−4.6, 2.4)^b^
Niewald 2022 34724085 | RT 3.0 Gy; Baseline to 3 months post RT; Follow-up, mo = 3 | Pain (VAS)^j^; Baseline:; N = 110 joints; M (SD) = 59.3 (16.7); Min = 10; Max = 90; Difference 3 months post RT:; N = 110 joints; MD (SD) = −18.9 (27.2); Min = −80; Max = 50; 95% CI = −23.98, −13.82^e^; Change in pain^j^, N^e^ (%):; Markedly improved = 46 (42); Improved = 19 (17); Stable = 26 (24); Worse = 19 (17); Knee injury and OA outcome score sum score—physical function short form (KOOS-PS)^k^; Baseline:; N = 32 joints; M (SD) = 20.5 (4.9); Min = 8; Max = 28; Difference 3 months post RT:; N = 32 joints; MD (SD) = −5.5 (5.9); Min = −19; Max = 7; 95% CI = −7.54, −3.46^e^; Short form score for the assessment and quantification of chronic rheumatic affections of the hands (SF-SACRAH); Baseline:; N =75 joints; M (SD) = 21.3 (10.6); Min = 3; Max = 46; Difference 3 months post RT:; N =74 joints; MD (SD) = −5.7 (10.5); Min = −38; Max = 7; 95% CI = −8.09, −3.31^e^ | Acute side effects (undefined), N (%) = 0 (0) | Short form 12 (SF-12), somatic scale, doctor’s judgement; Baseline:; N=68 joints; M (SD) = 29.8 (10.5); Min = 14; Max = 52; Difference 3 months post RT:; N=67 joints; MD (SD) = 5.7 (12.0); Min = −25; Max = 36; 95% CI = 2.83, 8.57^e^; Short form 12 (SF-12), psychic scale, doctor’s judgement; Baseline:; N = 68 joints; M (SD) = 56.0 (5.8); Min = 32; Max = 72; Difference 3 months post RT:; N = 67 joints; MD (SD) = 1.2 (6.5); Min = −16; Max = 23; 95% CI = −0.36, 2.76^e^; Short form 12 (SF-12), somatic scale, patient’s judgement; Baseline:; N=68 joints; M (SD) = 30.3 (11.1); Min = 15; Max = 52; Difference 3 months post RT:; N=67 joints; MD (SD) = 5.1 (10.2); Min = −25; Max = 31; 95% CI = 2.66, 7.54^e^; Short form 12 (SF-12), psychic scale, patient’s judgement; Baseline:; N = 68 joints; M (SD) = 57.8 (6.7); Min = 43; Max = 72; Difference 3 months post RT:; N=67 joints; MD (SD) = 0.1 (6.9); Min = −16; Max = 14; 95% CI = −1.55, 1.75^e^
Niewald 2022 34724085 | RT 0.3 Gy; Baseline vs 3 months post RT; Follow-up, mo = 3 | Pain (VAS)^i^; Baseline:; N=110 joints; M (SD)= 57.1 (15.0); Min = 20; Max = 90; Difference 3 months post RT:; N =110 joints; MD (SD) = −15.8 (25.5); Min = −70; Max = 60; 95% CI = −20.57, −11.04^e^; Change in pain^j^, %:; Markedly improved = 44 (40); Improved = 21 (19); Stable = 23 (21); Worse = 22 (20); Knee injury and OA outcome score sum score—physical function short form (KOOS-PS)^k^; Baseline:; N = 29 joints; M (SD) = 19.9 (4.6); Min = 8; Max = 27; Difference 3 months post RT:; N = 29 joints; MD (SD) = −4.9 (5.7); Min = −15; Max = 8; 95% CI = −6.98, −2.83^e^; Short form score for the assessment and quantification of chronic rheumatic affections of the hands (SF-SACRAH); Baseline:; N = 80 joints; M (SD) = 20.7 (10.4); Min = 5; Max = 50; Difference 3 months post RT:; N = 80 joints; MD (SD) = −4.4 (10.2); Min = −32; Max = 26; 95% CI = −6.64, −2.17^e^ | Acute side effects (undefined), N (%) = 0 (0) | Short form 12 (SF-12), somatic scale, doctor’s judgement; Baseline:; N=60 joints; M (SD) = 32.0 (9.6); Min = 17; Max = 52; Difference 3 months post RT:; N=60 joints; MD (SD) = 3.1 (10.5); Min = −18; Max = 32; 95% CI = 0.44, 5.76^e^; Short form 12 (SF-12), psychic scale, doctor’s judgement; Baseline:; N=60 joints; M (SD) = 57.4 (7.1); Min = 36; Max =73; Difference 3 months post RT:; N=60 joints; MD (SD) = 0.18 (7.4); Min = −18; Max = 20; 95% CI = −1.69, 2.05^e^; Short form 12 (SF-12), somatic scale, patient’s judgement; Baseline:; N=60 joints; M (SD) = 33.2 (10.0); Min = 18; Max = 52; Difference 3 months post RT:; N=60 joints; MD (SD) = 2.8 (0.6); Min = −19; Max = 29; 95% CI = 2.65, 2.95^e^; Short form 12 (SF-12), psychic scale, patient’s judgement; Baseline:; N=60 joints; M (SD) =56.7 (8.8); Min = 29; Max = 72; Difference 3 months post RT:; N=60 joints; MD (SD) = 0.03 (7.6); Min = −16; Max = 21; 95% CI = −1.89, 1.95^e^
Rühle 2021 34342662 | RT 3-6 Gy; Baseline vs follow-up; Follow-up, weeks = 8 | Pain (Pannewitz Score)^l^; Immediately following RT (N=1185 lesions), N (%); Complete pain relief = 18 (1.5); Partial pain relief = 693 (58.5); Unaltered pain = 428 (36.2); Increases in pain = 46 (3.9); Complete or partial pain response (Pannewitz Score)^l^; Immediately following treatment (N=1185 lesions), N (%); 711(60); Pain response (Pannewitz Score)^l^; approximately 8 weeks after RT (N=590 patients), N (%); Complete or partial = 387 (65.6); Stable pain = 166 (28.1); Increased pain = 37 (6.3); Pain (NRS), M (SD); Baseline = 66.0 (11.1); Immediately following RT = 53.4 (18.0); Approximately 8 weeks after RT = 44.5 (23.7); Baseline vs Immediately following RT p<0.001; Baseline vs 8 weeks after RT p<0.001; Pain (NRS), MD (SD) of patients with information at all timepoints (N=590); Baseline vs Immediately following RT = −12.3 (15.4); Baseline vs 8 weeks after RT = −21.0 (23.9)
Weissmann 2022 35046940 | RT 3-6 Gy; Baseline vs best therapeutic response of the patients immediately following the last RT session, as well as 3 and 6 months after RT, if available.; Follow-up, mo = Up to 6 | Improvement in pain levels (undefined) (N=196), N (%); 0-20% = 46 (23.5)^e^; 20-40% = 22 (11) 40-60% = 30 (15); 60-80% = 25 (12); 80-100% = 71 (37); Worsening of pain (N=196), N (%); 2 (1); Subjective improvement exceeding the clinical benchmark of 20% (N=196) N (%); 148 (75.5)

Notes.

a Copublication: Van den Ende, C.H., Minten, M.J., Leseman-Hoogenboom, M.M., van den Hoogen, F.H., Den Broeder, A.A., Mahler, E.A. and Poortmans, P.M., 2020. Long-term efficacy of low-dose radiation therapy on symptoms in patients with knee and hand osteoarthritis: Follow-up results of two parallel randomized, sham-controlled trials. The Lancet Rheumatology, 2(1), pp.e42–e49 38258275 ;

b Adjusted for stratification of NRS pain <8 vs ≥8/10;

c Adjusted for baseline values and stratification of pain, and pain medication;

d Scale of 0-10 where 0 represents the best outcome;

e Values calculated by the research team based on data provided in the article;

f Responde r= Either relative improvement in pain or function ≥50% and an absolute improvement of ≥20/100 points or 2 of the following: pain, function or patient’s global assessment (relative improvement ≥20% and ≥10/100 points absolute for pain and function or 1/10 points absolute for PGA);

g Adjusted for age BMI, PGA;

h Responder = Patients who improve in either pain or function with ≥50% (relative) and ≥20/100(absolute); or if improvement is ≥20% (relative) and ≥10/100 (absolute) for 2 of the following: pain, functioning, and PGA;

I Linear scale, 0 = no pain, 100 = maximum imaginable pain;

j Markedly improved = DeltaVAS ≥ 30 points, improved = 0<DeltaVAS<0;

k 0= No functional impairment; 100 = Maximum impairment;

l Complete response was considered a Pannewitz score = 0; Partial response was considered a Pannewitz score= 1-2; Unaltered response was considered a Pannewitz score = 3

Abbreviations. AE=adverse event; AOR=adjusted odds ratio; AUSCAN=Australian/Canadian Hand Osteoarthritis Index; BMI=body mass index; CI=confidence intervals; Gy=gray; KOOS-PS=Knee Injury and Osteoarthritis Outcome Score Sum Score- Physical Function Short From; M=mean; Max=maximum; MD=mean difference; Min=minimum; mo=months; NRS=numeric rating scale; OA=osteoarthritis; OMERACT-OARSI=Outcome Measures in Arthritis Clinical Trials - Osteoarthritis Research Society International; OR=odds ratio; PGA=Patient Global Assessment; QoL=quality of life; RT=radiation therapy; SD=standard deviation; SF-12=Short form 12; SF36=short form 36; SF-SACRAH=Short Form Score for the Assessment and Quantification of Chronic Rheumatic Affections of the Hand; VAS=visual analog scale; WOMAC=Western Ontario and McMaster University Osteoarthritis Index Scale.