# APPENDIX G PTERYGIUM

## APPENDIX G-1 PTERYGIUM DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Pterygium Brachytherapy Only
Viani, 2020, 22284040, Brazil | RCT | 2008-2009 | Teaching hospital, single center | Unclear | Fresh pterygium resected by a conjunctival autograft method and given b-radiotherapy within 3 days. Clinical diagnosis of pterygium after CAG surgery, without a previous surgery, or adjuvant treatments. | NR
Frucht, Pery, 1994, 8152772, Israel | RCT | 1989-1992 | Otherunclear, single center | Primary treatment/prevention of recurrence | 18 or older, recurrent pterygium or primary fleshy, and growing pterygium which invaded more than 2 mm into the cornea. | Atrophic primary pterygium.
Bekibele, 2004, 15587769, Nigeria | NRCS | 1999 | Non-teaching hospital, single center | Primary treatment/prevention of recurrence | NR | NR
Simşek, 2001, 11456012, Turkey | NRCS | NR | Other/unclear, NR/unclear | Primary treatment/prevention of recurrence | 18 or older, 2mm or more invasion of the cornea, primary or recurrent pterygium with active growth, symptomatic. | NR
Isohashi, 2006, 16896589, Japan | Single group | NR | Teaching hospital, single center | Primary treatment/prevention of recurrence | Complete surgical resection and received no other adjuvant | Not followed up for a period of at least 3 months and who had not received a total dose of at least 30 Gy.
Pterygium Not Brachytherapy
Willner, 2001, 11544903, Germany | Single group | 1987-2000 | Other/unclear, NR/unclear | Primary treatment/prevention of recurrence | NR | NR

Abbreviations. CAG=conjunctival autograft; Gy=gray; mm=millimeters; NR=not reported; NRCS=nonrandomized controlled study; PMID=PubMed ID; RCT=randomized controlled trial; RT=radiation therapy.

## APPENDIX G-2 PTERYGIUM BASELINE DATA

Author, Year, PMID | N Patients | Intervention | N Lesions | Follow-Up Treatment | Age | Male, N (%) | % White | Lesion Dimension (mm) | Lesion Location, N (%) | Other Information
Pterygium Brachytherapy Only
Viani, 2012, 22284040 | 96 | Conjunctival autografting followed by a total dose of 10Gy (SR90). | Surgery → RT = 54 | | 53 (21-88)^a^ | 47 (43.5) (eyes) | NR | 2.65^b,c^ | Nasal = 107 (99.0%)^c^; Temporal = 1(1.0%)^c^ | Grade, N (%) (eyes):^c^; I- 52 (48.1); II- 46 (42.6); III- 10 (9.3)
Viani, 2012, 22284040 | 96 | Conjunctival autografting. | Surgery = 54 | | 53 (21-88)^a^ | 47 (43.5) (eyes) | NR | 2.65^b,c^ | Nasal = 107 (99.0%)^c^; Temporal = 1(1.0%)^c^ | Grade, N (%) (eyes):^c^; I- 52 (48.1); II- 46 (42.6); III- 10 (9.3)
Frucht-Pery, 1994, 8152772 | Surgery → RT = 25 | Surgical excision followed by a total dose of 12Gy (SR90). | Surgery → RT = 25 | Steroids treatment for 3 months and topical antibiotics until epithelization was complete | 40.2 (18-61); 0 | 49 (65.3)^c^ | NR | NR | All located nasally | Recurrent Pterygium (at baseline):^c^ 19 (25.3%)
Frucht-Pery, 1994, 8152772 | Surgery → mitomycin C 0.01% = 25 | Surgical excision followed by mitomycin C (0.01%). | Surgery → mitomycin C 0.01% = 25 | Steroids treatment for 3 months and topical antibiotics until epithelization was complete | 40.2 (18-61); 0 | 49 (65.3)^c^ | NR | NR | All located nasally | Recurrent Pterygium (at baseline):^c^ 19 (25.3%)
Frucht-Pery, 1994, 8152772 | Surgery → mitomycin C 0.02% = 25 | Surgical excision followed by mitomycin C (0.02%). | Surgery → mitomycin C 0.02% = 25 | Steroids treatment for 3 months and topical antibiotics until epithelization was complete | 40.2 (18-61); 0 | 49 (65.3)^c^ | NR | NR | All located nasally | Recurrent Pterygium (at baseline):^c^ 19 (25.3%)
Bekibele, 2004, 15587769 | Surgery → RT = 24 | Surgical excision followed by 25-35 Gy (SR90). | Surgery → RT = 31 | | 46.5^b^ | 24 (50.0)^c^ | NR | NR | NR
Bekibele, 2004, 15587769 | Surgery → 5-FU = 24 | Surgical excision followed by 25mg/ml of 5-FU soak for 5 min. | Surgery → 5-FU = 27 | | 46.5^b^ | 24 (50.0)^c^ | NR | NR | NR
Simşek, 2001, 11456012 | Surgery → RT = 130 | Surgical excision followed by a total dose of 10-70Gy^d^ (SR90). | Surgery → RT = 141 | Antibiotic drops were prescribed during the first postoperative week and steroid drops (1% prednisolone acetate, qid) and artificial tear drops during the following month. | 42.6 (18-80)^a^ | 109 (56.5)^c^ | NR | NR | NR | Recurrent Pterygium (at baseline) (Lesions), N (%):; 91 (43.8)
Simşek, 2001, 11456012 | Surgery → Antineoplastic = 63 | Surgical excision followed by mitomycin C (0.02%) eyedrops four times a day up to one week | Surgery → Antineoplastic = 67 | Antibiotic drops were prescribed during the first postoperative week and steroid drops (1% prednisolone acetate, qid) and artificial tear drops during the following month. | 42.6 (18-80)^a^ | 109 (56.5)^c^ | NR | NR | NR | Recurrent Pterygium (at baseline) (Lesions), N (%):; 91 (43.8)
Isohashi, 2006, 16896589 | Surgery → RT = 1080 | Surgical excision followed by a total dose of 3035Gy (SR90). | Surgery → RT = 1253 | | 59 (16-90)^c^ | 556 (51.5) | NR | NR | Nasal = 1228 (98); Temporal = 25 (2) | Pterygium (at baseline) (lesions), N (%): Primary = 1,102 (87.9); Recurrent after surgery only =115 (9.2); Recurrent after surgery and RT 36 (2.9)
Pterygium Not Brachytherapy
Willner, 2001, 11544903 | N = 65 patients | 7Gy immediately pre-excision and 5Gy within 24 hours post-excision and every other day for a total dose of 17-27Gy, or 5Gy post-excision for a total dose of 5-30Gy started within 0-15 days and completed within 13 days | RT → Surgery → RT = 47 pterygium; or; Surgery → RT = 34 pterygium | | 53.7 (eye)^b,c^ | 48 (73.8 (of patients)^c^ | North European = 68 (84.0%) (of eyes); Mediterr anean = 13 (16.0%) (of eyes) | NR | Nasal =71 (87.7%) (of pterygium); Temporal = 10 (12.3%) (of eyes)

Notes.

a Mean (range);

b Mean (SD);

c Values calculated by the research team based on data provided in the article;

d <5% of patients receive between 51 and 70 Gy.

Abbreviations. 5-FU=5-fluorouracil; Gy=gray; mg=milligram; ml=milliliter; NR=not reported; PMID=PubMED ID; RT=radiation therapy.

## APPENDIX G-3 PTERYGIUM QUALITY RATING

Author, Year, PMID, Design | Random sequence | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall RoB
Pterygium - Brachytherapy Only
Viani, 2020, 22284040, RCT | Unclear | Yes (Low concern) | No (High concern)^a^ | Yes (Low concern) | No (Low Concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Low (RCT)
Frucht, Pery, 1994, 8152772, RCT | Yes (Low concern) | Unclear | No (High concern)^a^ | Yes (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Low (RCT)
Bekibele, 2004, 15587769, NRCS | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern)^b^ | No (Low concern) | Medium (NRCS)
Simşek, 2001, 11456012, NRCS | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (High concern)^c^ | No (Low concern) | High (NRCS)
Isohashi, 2006, 16896589, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single Group)^d^
Pterygium - Not Brachytherapy
Willner, 2001, 11544903, Single group | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | No (Low concern) | High (Single Group)^d^

Notes.

a Participants unable to be blinded to treatment;

b Match for age and sex;

c Crude analysis;

d The study design is unable to estimate the effect of RT on outcomes.

Abbreviations. NA=not applicable; NRCS: nonrandomized controlled study; PMDI=PubMed ID; RCT=randomized controlled trial.

## APPENDIX G-4 PTERYGIUM RESULTS SUMMARY

Author, Year, PMID | Comparison | Efficacy | Cosmetic | Patient Satisfaction/Experience/QoL | Complication/Side Effects
Pterygium - Brachytherapy Only
Viani, 2012, 22284040 | Surgery → RT(10Gy); vs Surgery; Follow-up, Mean (range), mo = 18 (6-26) | Recurrence (N=54 vs 54 eyes), [Mean 18mo], N (%); 5 (9.3) vs 12 (22.2); OR (95% CI) = 0.36 (0.12, 1.10)^a^; PT symptoms – improvement, [Mean 18mo], N (%)^a^; Improvement = 39 (72) vs 27 (50); Partial = 11 (20) vs 15 (28); No improvement = 4 (8) vs 12 (22); p=0.001; Received salvage surgery (eyes), N (%)^a^; Surgery + RT = 6 (11.1); Surgery alone = 7 (13.0); OR (95% CI) = 0.84 (0.26, 2.68) | Cosmetic results (not defined) [Mean 18mo], N (%)^a,b^; Excellent/good = 51 (94.4) vs 46 (85.2); Not satisfactory = 3 (5.6) vs 8 (14.8); p=0.03 | NR | NR
Frucht-Pery, 1994, 8152772 | Surgery → RT(12Gy); vs Surgery → MMC 0.01%; Follow-up, Mean (range), mo = 15.3 (7-27) | Recurrence (N=25 vs 25), [Mean 15.3 mo], N (%); 5 (20.0) vs 2 (8.0); OR (95% CI) = 2.88 (0.50, 16.48)^a^ | NR | NR | During the first three postoperative weeks, all patients had complaints of ocular pain, photophobia and lacrimation.; Delay in conjunctival healing for 8 weeks postop, N; MMC 0.02% = 1 (patient had recurrent pterygium); Calcified degeneration of conjunctiva in the operated area, N; MMC 0.02% = 1 (patient had 5 previous pterygium surgeries and previous RT)
Frucht-Pery, 1994, 8152772 | Surgery → RT(12Gy); vs Surgery → MMC 0.02%; Follow-up, Mean (range), mo = 15.3 (7-27) | Recurrence (N=25 vs 25), [Mean 15.3mo], N (%); 5 (20.0) vs 1 (4.0); OR (95% CI) = 6.00 (0.65, 55.66)^a^ | NR | NR
Bekibele, 2004, 15587769 | Surgery → RT (25-35 Gy); vs Surgery → 5-FU; Follow-up, Mean (range), mo = 9.5 (2 wk- 2 y)^a^ | Recurrence (N=31 vs 27 eyes), [4mo to 1y], N (%); 7 (22.5) vs 7 (25.9); unadOR (95% CI) = 0.83 (0.25, 2.78)^a^; Visual acuity changes (Snellen lines) (N=31 vs 27 eyes), N (%)^a^; Improvement of 2+ lines = 0 (0.0) vs 9 (33.3); Reduction of 1 to 2 lines = 0 (0.0) vs 2 (7.5) | Cosmetically unacceptable recurrence (N=31 vs 27 eyes), [4mo to 1y], N (%); 2 (6.5) vs 3 (11.1); unadOR (95% CI) = 0.55 (0.09, 3.58)^a^ | NR | Cornea opacity (N= 31 vs 27), [4mo to 1y], N (%); 1 (3.2) vs 10 (37.0); unadOR (95% CI) = 0.06 (0.01, 0.48)^a^; Conjunctivitis (N= 31 vs 27), [4mo to 1y], N (%); 3 (9.7) vs 3 (11); unadOR (95% CI) = 0.86 (0.16, 4.65)^a^; Cornea necrosis (N= 31 vs 27), [4mo to 1y], N (%); 0 (0) vs 1 (3.7); RD (95% CI) = −0.04 (−0.11, 0.03)^a^; Sclera granuloma(N= 31 vs 27), [4mo to 1y], N (%); 0 (0.0) vs 3 (11.1); RD (95% CI) = −0.11 (−0.23, 0.07)^a^
Simşek, 2001, 11456012 | Surgery → RT(10-70Gy); vs Surgery → Antineoplastic; Follow-up, Mean (range), mo = 52 (3- 144)^a^ | Recurrence (N=141 vs 67 eyes), [2-12 mo], N (%); 9 (6.4) vs 12 (17.9); unadOR (95% CI) = 0.31 (0.12, 0.78)^a^ | NR | NR | Almost all patients complained about pain photophobia, tearing and foreign body sensation after Sr-90 treatment in the first postoperative week.; Almost all patients treated with MMC complained of burning and foreign body sensation, tearing and photophobia during treatment.; Complications (N= 141 vs 67 eyes), N (%):; Lense opacity = 4 (2.8) vs 0 (0.0); Scleral melting = 3 (2.1) vs 6 (9.0); Conjunctival scar formation = 3 (2.1) vs 0 (0.0); Granuloma formation = 1 (0.7) vs 0 (0.0); Iris prolapse = 1 (0.7) vs 0 (0.0); Punctate keratopathy = 0 (0.0) vs 4 (6.0); Purulent conjunctivitis = 0 (0.0) vs 2 (3.0); Corneal microabscess = 0 (0.0) vs 1 (1.5); Increased pigmentation = 0 (0.0) vs 1 (1.5); More complications were seen in [the excision plus MMC arm] = p<0.001
Isohashi, 2006, 16896589 | Surgery → RT(30-35Gy); Follow-up, Median (range), mo = 45 (3-120)^a^ | Recurrence (N= 1253), [Median 45mo], N (%); 97 (7.7) | NR | NR | Side effects (N=1253), [3mo], N (%); Moderate conjunctivitis = 2 (0.2); Local pain = 60 (4.9); Visual disturbance = 71 (5.7); Photophobia or an increase in tear flow = 58 (5.6); No severe late complications, such as scleral ulcer, scleral necrosis and scleromalacia, were encountered.
Pterygium - Not Brachytherapy
Willner, 2001, 11544903 | RT → Surgery → RT = 47; or; Surgery → RT = 34; Follow-up, Mean, mo = 32 | Recurrence (New pterygium at the same site diagnosed by an ophthalmologist) by treatment (Mean 32 months), N(%)^a^; 4 (8.5) vs 15 (44.1); unadOR (95% CI) = 0.12 (0.03, 0.40) | | | Only conjunctivitis and superficial keratitis was transiently observed within the first days following treatment.; [At publication] no case of severe side effects like scleral necrosis or thinning, symblepharon, radiation-induced cataract or glaucoma were observed in both groups.

Notes.

a Values calculated by the research team based on data provided in the article;

b Unit of analysis was unclear, which we inferred was eyes.

Abbreviations. CI=confidence interval; Gy=gray; MMC=mitomycin C; mo=months; PMID=PubMed ID; QoL=quality of life; RD=risk difference; RT=radiation therapy; unadOR=unadjusted odds ratio; wk=weeks, y=year.