# APPENDIX F PLANTAR FASCIITIS

## APPENDIX F-1 PLANTAR FASCIITIS DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Gogna, 2016, 27521483; India | RCT | NR | Teaching hospital | Primary treatment/prevention of recurrence | Patients who were diagnosed with plantar fasciitis and failed conservative treatment (activity modification, ice packs, NSAIDs, orthotics, and plantar fascia and tendoachilles stretching) for 6 months were identified and included in the study. | Patients with diabetes mellitus, gout, generalized inflammatory arthritis (Rheumatoid arthritis, Ankylosing spondylitis, Psoriatic arthritis), malignancy, pregnancy, bleeding diathesis, radiculopathy, and those who had received local steroid injections within the last 6 months
Canyilmaz, 2015, 25936814; Turkey | RCT | 2013-2014 | Teaching hospital | Primary treatment/prevention of recurrence | Patients were included if they met the following criteria: (1) symptoms and clinical diagnosis of a painful heel spur; (2) duration of symptoms longer than 6 months; (3) radiologically proven heel spur; (4) Karnofsky performance status 70; and (5) age 40 years | Patients who had previous radiation therapy, trauma to the foot, severe psychiatric disorders, rheumatic and/or vascular diseases, or were pregnant or breastfeeding
Aynaci, 2021; Turkey | NRCS | 2013-2017 | Teaching hospital | Primary treatment/prevention of recurrence | Confirmed diagnosis of PF with Karnofsky performance status ≥70, presenting with pain and/or mobility restrictions | Trauma to the foot, severe psychiatric disorders, rheumatic and/or vascular diseases, and pregnancy or breastfeeding
Rudat 2021, 33502569; Germany | Single group | 2009-2020 | Other/unclear | Primary treatment/prevention of recurrence | Patients treated with LD-EBRT for painful plantar heel spurs during the study dates | Patients with a previous LD-EBRT for painful PCS
Hermann 2013 24120823; Germany | Single group | 2007-2009 | Other/unclear | Primary treatment/prevention of recurrence | Localized plantar heel pain, irrespective of its radiologic evidence, not undergone surgery or radiation therapy within the previous 3 years | NR

Abbreviations. LD-EBRT=low-dose external beam radiotherapy; NSAID=non-steroidal anti-inflammatory; NRCS=nonrandomized comparative study; NR=not reported; RCT=randomized controlled trial; RT=radiation therapy; mo=month; PMID=PubMed ID; PCS=plantar calcaneal spurs.

## APPENDIX F-2 PLANTAR FASCIITIS BASELINE DATA

Author, Year, PMID | N Patients | Intervention | N Lesions | Age Mean(SD) | N (%) Male | N (%) White | Lesion Characteristics
Author, Year, PMID | N Patients | Intervention | N Lesions | Age Mean(SD) | N (%) Male | N (%) White | Location | Lesion Age | Size (mm) | Previous Treatment | Other
Gogna, 2016, 27521483 | RT = 20 | Total of 3.0 Gy radiation applied as 0.5 Gy twice weekly | NR | 27.58 (NR)^a^ | 16 (65)^a^ | NR | Foot | >6 mo | NR | All failed conservative treatment for 6 mo | All sports persons
Gogna, 2016, 27521483 | Plasma = 20 | Platelet Rich Plasma | NR | 27.58 (NR)^a^ | 16 (65)^a^ | NR | Foot | >6 mo | NR | All failed conservative treatment for 6 mo | All sports persons
Canyilmaz, 2015, 25936814 | RT = 60 | 6 fraction of 1 Gy 3× per week for 2 weeks for a total dose of 6 Gy using a 6 mv photon beam of a linear accelerator | NR | Mean (range) = 53.65 (4074)^a,b^ | 27 (21.8)^a^ | NR | Plantar = 83 (66.9)^a^; Dorsal = 20 (16.1)^a^; Both = 21 (16.9)^a^ | Pain duration (mo), Mean (SD): 16.3 (6-48)^a^; Duration of pain (mo), N (%)^a^; ≤6 = 34 (27.4); >6 = 90 (72.6) | NR | Previous treatment, N (%)^a^; Ice/heat= 13 (10.5); Extracorporeal shock wave = 26 (21.0); Oral medication = 17 (13.7); Injection = 38 (30.7); Insole support t = 21 (16.9); Ultrasound application = 9 (7.3); All had recurrent symptoms after previous conservative treatments.
Canyilmaz, 2015, 25936814 | Palpation-guided steroid injection = 64 | 40 mg methylprednisolone mixed with 0.5ml of 1% lidocaine | NR | Mean (range) = 53.65 (4074)^a,b^ | 27 (21.8)^a^ | NR | Plantar = 83 (66.9)^a^; Dorsal = 20 (16.1)^a^; Both = 21 (16.9)^a^ | Pain duration (mo), Mean (SD): 16.3 (6-48)^a^; Duration of pain (mo), N (%)^a^; ≤6 = 34 (27.4); >6 = 90 (72.6) | NR
Aynaci^c^, 2021 | Extracorporeal shock-wave therapy = 73 | 2000 (11 times per sec) shockwave impulses (20 MHz) at 3 bar air pressure were delivered using a 16-mm head, carried out in 5 sessions with weekly intervals. | NR | Mean (range) = 50.4 (2678)^b^ | 15 (20.5)^c^ | NR | Plantar = 36 (49.3); Dorsal = 2 (2,7); Both = 3 (4.1); Achillodynia = 12 (16.4); Calcaneodynia = 20 (27.4) | Duration of pain (mo), Mean (range) = 16,4 (1-96); Duration of pain (mo), N (%); ≤6 = 21 (29.2); >6 = 52 (70.8) | NR | All patients had received various treatments previously.
Rudat 2021, 33502569 | RT = 666 | LD-EBRT:; 0.5 Gy 3 times a week to a total of 3.0 Gy or 1 Gy 3 times a week to a total of 6.0 Gy | 864 | 56.9 (20-95) | 217 (32.6) | NR | Treatment, N (%); Bilateral (concomitantly) = 123 (18.5); Right and left heel sequentially 79 (11.9); Right heel = 223 (33.5); Left heel = 241 (36.2) | History of pain before RT (heels) (mo), N (%); <6 = 285 (40.7); 6–12 = 242 (34.5); >12 = 174 (24.8%) | NR | Most patients received multiple conservative treatments before referral to [radiotherapy]. | Re-irradiation 3 mo after previous RT treatment; Re-RT1 = 238; Re-RT2 = 48; Re-RT3 = 6
Hermann-2013-24120823 | 250 | 44 heels: single dose of 0.5 Gy (total dose, 3 Gy).; 241 patients: 1 Gy 2 times per week (total dose, 6 Gy All: 6 MVX photons | 285 | Median (range) = 53 (23-86) | 71 (28.4) | NR | NR | Onset of pain:; <6mo = 75 (26); 6-12 mo = 74 (26); >12 mo = 120 (42); Not known = 16 (6) | Mean length of heel spur (mm)= 6.5 mm (range 0.6-25) | Prior radiation therapy >3 years = 16 (8); Insole support = 156 (75); Local injections = 84 (41); Extracorporeal shock waves = 44 (21); Systemic NSAIDs =133 (64) | Comorbidities:; Foot deformities = 127 (45); Endoprosthesis = 16 (6); Diabetes = 9 (3)

Notes.

a Values calculated by the research team based on data provided in the article;

b Mean (range);

c Only includes data from the ESWT arm.

Abbreviations. Gy=gray; mo=month; LD-EBRT=low-dose external beam radiotherapy; MHz=megahertz; ml=milliliters; mm=millimeter; mv=megavolt; MVX=megavoltage x-rays; NR=not reported; NSAIDs=nonsteroidal anti-inflammatory drugs; PMID=PubMed ID; RT=radiation therapy; SD=standard deviation.

## APPENDIX F-3 PLANTAR FASCIITIS QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants and study personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall RoB
Gogna, 2016, 27521483, RCT | Yes (Low concern) | Unclear | No (High concern) | Unclear | No (Low Concern) | No (Low Concern) | Yes (Low Concern) | No (High concern)^a^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low Concern) | Medium (RCT)
Canyilmaz, 2015, 25936814, RCT | Yes (Low concern) | Unclear | No (High concern) | No (High concern) | No (Low Concern) | No (Low Concern) | Yes (Low Concern) | No (High concern)^b^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low Concern) | Medium (RCT)
Aynaci, 2021 Turkey, NRCS | NA | NA | NA | Unclear | No (Low Concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (High concern)^c^ | Unclear | Yes (Low concern) | No (High concern)^d^ | No (Low Concern) | High (NRCS)
Rudat 2021, 33502569, Single group | NA | NA | NA | Unclear | No (Low Concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | Yes (High Concern)^e^ | High (Single Group) ^f^
Hermann-2013-24120823 | NA | NA | NA | No (High concern) | No (Low Concern) | NA | NA | No (Low concern) | No (Low concern) | No (Low concern) | No (Low concern) | No (Low concern) | NA | NA | No (Low Concern) | High (Single Group) ^f^

Notes.

a Dates of study not reported and lack of clarity surrounding comparisons reported in results;

b Unclear whether follow-up measures were reported as mean or medians difference;

c Unclear about which pain measures were reported;

d Crude analysis;

e 30% of patients lost to follow-up at 3 months;

f The study design is unable to estimate the effect of RT on outcomes.

Abbreviations. NA=Not applicable; NRCS=nonrandomized comparative study; RCT=randomized controlled trial.

## APPENDIX F-4 PLANTAR FASCIITIS RESULTS SUMMARY

Author, Year, PMID | Comparator | Efficacy | Side Effects | Patient Satisfaction/Experience/QoL
Gogna, 2016, 27521483 | RT 3.0 Gy vs PRP; or Baseline vs follow-up; Follow-up, mo = 3 and 6 | Pain (VAS), (N = 20 vs 20), Mean (SD); Baseline = 6.5 (0.889) vs 6.65 (0.819); 3mo = 2.55 (NR) vs 2.45 (NR); 6mo = 2.35 (0.745) vs 2.25 (0.639); Pain (VAS), (N = 20 vs 20), p-value (between group); 3mo = 0.6093; 6mo = 0.6510; Mean decrease in Pain (VAS), Baseline vs 6mo 4.15 vs 4.40; Net change (between-group) = 0.25 (−0.238, 0.738) p = 0.315^a^; Difference in Pain (VAS), p-value (within-group); PRP Baseline vs PRP 3mo = <0.0001; PRP 3mo vs PRP 6mo = <0.1625; RT Baseline vs RT 3mo = 0.0001; RT 3mo vs RT 6mo = NR; Difference in Pain (VAS), Baseline vs 6mo (within-group); PRP Net change = −4.4 (−4.725, −4.075), p<0.001^a^; RT Net change = −4.15 (−4.512, −3.788), p<0.001^a^; Plantar fasciitis thickness (mm), (N = 20 vs 20), Mean (SD)^a^; Baseline = 6.71 (0.290) vs 6.765 (0.308); 6mo = 5.62 (0.353) vs 5.585 (0.315); Net change = 0.09 (−0.108, −0.288) p = 0.372; Difference in Planta fasciitis thickness (mm), (N = 20 vs 20), p-value (between group); Baseline to 3mo = NS; Difference in Planta fasciitis thickness (mm), p-value (within group); PRP Baseline vs PRP 6mo = <0.0001; RT Baseline vs RT 6mo = <0.0001; American Orthopedic Foot and Ankle Score, (N = 20 vs 20), mean (SD)^a^; Baseline = 52.5 (7.674) vs 51.5 (8.751); 6mo = 89.65 (3.528) vs 89.1 (3.626); Net Change = −0.45 (−4.397, 3.497) p = 0.823; Difference in American Orthopedic Foot and Ankle Score, PRP (N = 20 vs 20), p-value (between group); Baseline to 3mo = 0.6290; Baseline to 6mo = NS; Difference in American Orthopedic Foot and Ankle Score, p-value (within group); PRP Baseline vs PRP 6mo = <0.0001; RT Baseline vs RT 6mo = <0.0001 | Initial worsening of pain in the 1 to 2-week period post-radiation followed by progressive improvement, N; 5 vs 0
Canyilmaz, 2015, 25936814 | RT 6 Gy vs PGSI; Follow-up, Median (range), mo = 12.5 (6.5-18.5) | Pain (VAS), (N = 60 vs 64); Baseline:; Mean = 7.6 vs 6.9; Min = 4 vs 4; Max = 10 vs 10; Median = 8 vs 7; p = 0.009; 3 mo follow-up:; Mean = 2.8 vs 4.6; Min = 0 vs 0; Max = 9 vs 10; Median = 2 vs 5; p<0.001; 6 mo follow-up:; Mean = 2.7 vs 4.6; Min = 0 vs 0; Max = 10 vs 10; Median = 2 vs 5; p<0.001; Modified von Pannewitz pain score, (N = 60 vs 64), N (%); Response at 3 mo follow-up:; Complete = 23 (38.3) vs 10 (15.6); Partial = 17 (28.3) vs 6 (9.4); Minor = 11 (18.3) vs 22 (34.4); No change = 8 (13.3) vs 20 (31.3); Increased pain = 1 (1.7) vs 6 (9.4); p<0.001; Response at 6mo follow-up:; Complete = 21 (35) vs 10 (15.6); Partial = 20 (33.3) vs 8 (12.5); Minor = 12 (20) vs 20 (31.3); No change = 6 (10) vs 20 (31.3); Increased pain = 1 (1.7) vs 6 (9.4); p<0.001; Five-level function score, (N = 60 vs 64); Baseline:; Mean = 41.6 vs 48.4; Min = 20 vs 30; Max = 70 vs 85; Median = 40 vs 50; p<0.001; 3mo follow-up:; Mean = 78.3 vs 60; Min = 30 vs 6; Max = 100 vs 100; Median = 85 vs 57.5; p<0.001; 3mo, N (%):^b^; Excellent = 24 (40) vs 10 (15.6); Good = 24 (40) vs 12 (18.8); Moderate = 12 (20) vs 32 (50); Poor = - vs 10 (15.6); 6mo follow-up:; Mean = 78.7 vs 59; Min = 35 vs 0; Max = 100 vs 100; Median = 80 vs 60; p<0.001; 6mo, N (%):^b^; Excellent = 23 (38.3) vs 10 (15.6); Good = 23 (38.3) vs 14 (21.9); Moderate = 13 (21.7) vs 29 (45.3); Poor = 1 (1.7) vs 11 (17.2); Pain relief, RT vs PGSI (Time not specified)^c^; HR (95%CI) = 1.89 (0.88, 4.04), p = 0.102; Time interval required for second treatment (mo), RT vs PGSI:; Mean = 9 vs 6.4; Min = 4 vs 3.1; Max = 15.2 vs 14.1; p = 0.045; 1-year probability of patients not requiring a second treatment:; 95% vs 90.2% | Acute infection at injection site; PGSI group = 1; Acute side effects or long-term toxicity did not occur in the radiation therapy arm.
Aynaci, 2021 | RT 6 Gy vs PGSI vs ESWT; Follow-up, Median (range), mo = 15.5 (6.5-37.4) | Pain (VAS), (N = 67 vs 65 vs 73); Baseline:; Mean = 7.7 vs 6.9 vs 7.5; Min = 4 vs 4 vs 4; Max = 10 vs 10 vs 9; Median = 8 vs 7 vs 8; Overall p = 0.004; RT vs ESWT p = 0.347; 3mo follow-up:; Mean = 2.5 vs 4.6 vs 4.1; Min = 0 vs 0 vs 0; Max = 9 vs 10 vs 9; Median = 2 vs 5 vs 4; Overall = p<0.001; RT vs ESWT = (p<0.001); 6mo follow-up:; Mean = 2.5 vs 4.6 vs 3.6; Min = 0 vs 0 vs 0; Max = 10 vs 10 vs 10; Median = 2 vs 5 vs 3; Overall p<0.001; Pain control (free of pain, considerable, and some improvement) (not specified) (time not specified), %; 80.6 vs 72.3 vs 63; Modified von Pannewitz pain score, (N = 67 vs 65 vs 73), N (%); Response at 3 mo follow-up:; Complete = 28 (41.8) vs 10 (15.4) vs 11 (15.1); Partial = 20 (29.9) vs 7 (10.8) vs 20 (27.4); Minor = 10 (14.9) vs 22 (33.8) vs 27 (37); No change = 8 (11.9) vs 20 (30.8) vs 15 (20.5); Increased pain = 1 (1.5) vs 6 (9.2) vs –; Overall p<0.001; Response at 6 mo follow-up:; Complete = 26 (40) vs 10 (15.4) vs 16 (21.9); Partial = 21 (32.3) vs 9 (13.8) vs 23 (31.5); Minor = 11 (16.9) vs 20 (30.8) vs 20 (27.4); No change = 6 (9.2) vs 20 (30.8) vs 14 (19.2); Increased pain = 1 (1.5) vs 6 (9.2) vs –; Overall p<0.001; Five-level function score, (N = 67 vs 65 vs 73); Baseline:; Mean = 40.9 vs 48.4 vs 41.9; Min = 20 vs 30 vs 20; Max = 70 vs 85 vs 80; Median = 40 vs 50 vs 45; Overall p<0.001; 3mo follow-up:; Mean = 80.4 vs 60.2 vs 65.6; Min = 30 vs 6 vs 30; Max = 100 vs 100 vs 100; Median = 85 vs 60 vs 65; Overall p<0.001; 3mo, N (%):^d^; Excellent = 31 (46.3) vs 10 (15.6) vs 14 (19.2); Good = 24 (35.8) vs 13 (20) vs 6 (8.2); Moderate = 12 (17.9) vs 32 (49.2) vs 49 (67.1); Poor = - vs 10 (15.6) vs 4 (5.5); 6mo follow-up:; Mean = 80.3 vs 59.2 vs 68.6; Min = 35 vs 0 vs 30; Max = 100 vs 100 vs 100; Median = 85 vs 60 vs 65; Overall = p<0.001; 6mo, N (%):^d^; Excellent = 28 (43.1) vs 10 (15.4) vs 17 (23.3); Good = 23 (35.4) vs 15 (23.1) vs 9 (12.3); Moderate = 13 (20) vs 29 (44.6) vs 44 (60.3); Poor = 1 (1.5) vs 11 (16.9) vs 3 (4.1); Time interval required for second treatment (mo), (N = 67 vs 65 vs 73), Mean (range); 9 (4,14.1) vs 6.4 (2.1, NR) vs 7.8 (3.1,13.9); Overall p = 0.069; Required second treatment, PGSI vs RT (time unclear)^c^; HR (95%CI) = 0.41 (0.2, 0.86), p = 0.018 | Arm pain during treatment; ESWT = 10; Reddening of the skin (time not specified); ESWT = 2
Rudat 2021, 33502569 | RT 3.0-6.0 Gy; Baseline vs follow-up; Follow-up, Median (range), mo = 16 (3-125) | Patients who achieved pain reduction of 75%-100% (VAS) (N =864 heels), N (%)^a^; Last day of RT = 268 (31); 3mo after RT = 553 (64); 12mo after RT = 588 (68); 24mo after RT = 605 (70); 36mo after RT = 536 (62); >36mo after RT = 562 (65); Probability of insufficient pain control (pain reduction of less than 75%) at 10 years: 45.9% (39.4, 52.4%); Opted for re-irradiation for stronger pain reduction 3m post-RT, N (%) (864 heels); No Re-RT = 572 (66.2); Re-RT 1 = 238 (27.5); Re-RT 2 = 48 (5.6); Re-RT 3 = 6 (0.7) | Apart from the initial increase in pain during and shortly after [RT], toxicity clearly attributable to acute or late radiation reactions was not observed in any patient.
Hermann-2013-24120823 | RT 3 or 6 Gy; Baseline vs follow-up; Follow-up, Mean (range), mo = 11 (1-57) | Symptom remission (not defined) (N =285 heels), N (%); Complete remission = 107 (38); Partial remission = 91 (32); No change = 54 (19); Unknown = 33 (11); Symptom remission (not defined) by total Gy (N = 285 heels), N (%); 3 Gy (N =44); Complete remission = 12 (27); Partial remission = 18 (41); No change = 7 (16); Not known = 7 (16); 6 Gy (N =241); Complete remission = 95 (40); Partial remission = 73 (30); No change = 47 (20); Not known = 26 (10) | NR | NR

Notes.

a Values calculated by the research team based on data provided in the article;

b Excellent = 90-100 points; Good = 70-85 points; Fair = 40-69 points; and Poor = 0-39 points;

c Model adjusted for age, sex, BMI, and duration of pain;

d Excellent = 90-100 points; Good = 70-89 points; Fair = 40-69 points; Poor = 0-39 points.

Abbreviations. CI=confidence interval; ESWT=extracorporeal shock-wave therapy; Gy=gray; y=years; HR=hazard ratio; Max=maximum; Min=minimum; mm=millimeters; mo=month; NR=not reported; NS=not significant per article text; PGSI=palpation guided steroid injection; PMID=PubMed ID; PRP=plasma rich protein; QoL=quality of life; RT=radiation therapy; SD=standard deviation; VAS=Visual Analog Scale.