# APPENDIX E KELOIDS

## APPENDIX E-1 KELOIDS DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Akinbiyi, 2021, 32878694, USA | NRCS | 2008 - 2017 | Single center, teaching hospital | Primary treatment/prevention of recurrence | Adults with ICD-10 codes corresponding to keloid who were treated by physicians in the plastic surgery or dermatology departments. | <1 year follow-up and those treated with other oral or topical agents (for medical management group)
Aluko-Olokun, 2014, Nigeria | RCT | 2005 - 2006 | Single center other/unclear | Primary treatment/prevention of recurrence | NR | Infected or ulcerated lesions, chronic inflammatory conditions (eg, tuberculosis and other chronic granulomatous conditions), children under 6 years of age, pregnancy, immunosuppressive state, high blood pressure, glaucoma, epilepsy, Myasthenia gravis, cancer, and non-consenting patients
Khalid, 2018, 29534885, Pakistan | RCT | 2014 - 2015 | Teaching hospital, single center | Primary treatment/prevention of recurrence | 12-65y | Treatment in the last 6 months, history of renal or liver disease, and being pregnant or lactating
Li, 2022, 36582847, China | RCT | 2021 - 2021 | Teaching hospital, single center | Primary treatment/prevention of recurrence | Age 18–70, did not experience any keloid treatment within 3 months, lesions without progression within 3 months, and assessed by the VSS with a score more than 4 and less than 13. | Pregnancy and lactation, systemic disease or tumor, infection of lesions, allergic to corticosteroids or 5-FU
Qiao, 2017, 29798227, China | NRCS | 2007 - 2016 | Teaching hospital/other/unclear, single center | Primary treatment/prevention of recurrence | Patients with ear scars admitted to Shanxi Provincial People’s Hospital | NR
Sclafani, 1996, 8646474, USA | RCT | 1991 - 1996 | Teaching hospital, single center | Primary treatment/prevention of recurrence | Keloid patients seen from Oct 1991-Dec 1992 at the New York Eye & Ear Infirmary with ear keloid. | Patients who had previously received radiation therapy to the head and neck region.

Abbreviations. NRCS=non-randomized study; NR=not reported; RCT=randomized controlled trial; VSS=Vancouver Scar Scale; PMID=PubMed ID; RT=radiation therapy; ICD=International Classification of Diseases; 5-FU=5-fluoracil.

## APPENDIX E-2 KELOIDS BASELINE DATA

Author, Year, PMID | N Patients | Intervention | N Lesions | Age | N (%) Male | N (%) White | Keloid Characteristics
Author, Year, PMID | N Patients | Intervention | N Lesions | Age | N (%) Male | N (%) White | Location | Etiology | Lesion Age (Years) | Size | Other
Akinbiyi, 2021, 32878694 | Surgical excision → RT = 95 | 3-8 Gy per fraction, total dose of 9-32 Gy, 24-48 hours post-excision involving 3-4 sessions on consecutive days | NR | 37.2 (19.9)^a,b^ | 64^a^ (33.9) | 30^a^ (15.9) | Head, Neck, Back, Upper Torso; Lower Torso, Upper extremity, Lower extremity | NR | NR | Size of keloid (cm), median (IQR) surgical excision +RT (median, IQR) = 13.8 (6.7, 40.0); Surgical excision (median, IQR) = 6.1 (2.7, 15.0) | Recurrent keloids (at baseline), N (%) = 82 (43.3)^a^; History of keloids, N (%) = 115 (60.8)^a^
Akinbiyi, 2021, 32878694 | Surgical excision = 94 | Keloid local excision with or without prior or concurrent corticosteroid therapy, but without radiation therapy | NR | 37.2 (19.9)^a,b^ | 64^a^ (33.9) | 30^a^ (15.9) | Head, Neck, Back, Upper Torso; Lower Torso, Upper extremity, Lower extremity | NR | NR | Size of keloid (cm), median (IQR) surgical excision +RT (median, IQR) = 13.8 (6.7, 40.0); Surgical excision (median, IQR) = 6.1 (2.7, 15.0) | Recurrent keloids (at baseline), N (%) = 82 (43.3)^a^; History of keloids, N (%) = 115 (60.8)^a^
Aluko-Olokun, 2014 | Surgical excision → RT = 53 | One fraction pre-excision, 4 Gy pre-excision, 4 Gy per fraction, total dose of 16 Gy, 3 days post-excision | NR | 27.1^a,b^ | 59^a^ (55.1) | NR | Pinna, Cheek, Forehead, Subman-dibular, Lip | NR | NR | Pretreatment height (mm), mean = 7.5^a^
Aluko-Olokun, 2014 | Triamcinolone = 54 | Intralesional injections of 10 mg/cm of lesion for a maximum of 6 months | NR | 27.1^a,b^ | 59^a^ (55.1) | NR | Pinna, Cheek, Forehead, Subman-dibular, Lip | NR | NR | Pretreatment height (mm), mean = 7.5^a^
Khalid, 2018, 29534885 | Surgical excision → RT = 30 | 10 Gy in 2 fractions, total dose of 20 Gy, starting within 24 hours post-excision | 60 | 31.8 (6.6)^a,b^ | 16 (26.7)^a,b^ | NR | Ear 60(100):; Lobule only = 38(63.3)^a^;; Lobule and helix = 12 (20)^a^ | Related to ear piercing, N (%) = 42 (70)^a^ | 4.7^a^ | Size of scar: 5-FU+TAC= 2.3+ 0.98 cm; RT = 2.5+1.10cm | Previous treatments; Either (excision or intralesional injections), N (%) = 22 (36.67)^a^
Khalid, 2018, 29534885 | Surgical excision → 5-FU + triamcinolone acetonide = 30 | Intralesional injections of 150 mg in a monthly interval or until cure | 60 | 31.8 (6.6)^a,b^ | 16 (26.7)^a,b^ | NR | Ear 60(100):; Lobule only = 38(63.3)^a^;; Lobule and helix = 12 (20)^a^ | Related to ear piercing, N (%) = 42 (70)^a^ | 4.7^a^ | Size of scar: 5-FU+TAC= 2.3+ 0.98 cm; RT = 2.5+1.10cm | Previous treatments; Either (excision or intralesional injections), N (%) = 22 (36.67)^a^
Li, 2022, 36582847 | Surgical excision → RT = 17 | 3.5-4 Gy per fraction starting within 24 hours of surgery and on the second, third- and fourth-days post-excision, total dose of 14-16 Gy | NR | 32.2 (18.3)^a,b^ | 18 (32.8)^a^ | NR | Head and face, trunk, limbs | Acne, folliculitis, surgery, injury, spontaneous | 6.3 (5.8)^a,b^ | NR | Previous therapy, N (%) = 30 (54.5)^a^; Family history, N (%) = 49 (89.1)^a^
Li, 2022, 36582847 | Surgical excision → 5-FU + betamethasone = 18 | Injections of 2 mL 5-FU, 1 mL betamethasone, and 1 mL lidocaine immediately after excision and every 4 weeks post-excision, total of 4 injections | NR | 32.2 (18.3)^a,b^ | 18 (32.8)^a^ | NR | Head and face, trunk, limbs | Acne, folliculitis, surgery, injury, spontaneous | 6.3 (5.8)^a,b^ | NR | Previous therapy, N (%) = 30 (54.5)^a^; Family history, N (%) = 49 (89.1)^a^
Li, 2022, 36582847 | 5-FU + betamethasone = 20 | Intralesional injections of 2 mL 5-FU, 1 mL betamethasone, and 1 mL lidocaine every 4 weeks, total of 4 injections | NR | 32.2 (18.3)^a,b^ | 18 (32.8)^a^ | NR | Head and face, trunk, limbs | Acne, folliculitis, surgery, injury, spontaneous | 6.3 (5.8)^a,b^ | NR | Previous therapy, N (%) = 30 (54.5)^a^; Family history, N (%) = 49 (89.1)^a^
Qiao, 2017, 29798227 | Surgical excision = 40 | Keloid local excision | NR | NR | 25.1 | NR | Earlobe, helix, and the whole pinna | Ear piercing, trauma, ear surgery | 1-15^c^ | NR
Qiao, 2017, 29798227 | Surgical excision → diprosone = 40 | Corticosteroid injection locally during excision | NR | NR | 25.1 | NR | Earlobe, helix, and the whole pinna | Ear piercing, trauma, ear surgery | 1-15^c^ | NR
Qiao, 2017, 29798227 | Surgical excision → RT = 40 | 5Gy per fraction, total dose of 15Gy, post-excision | NR | NR | 25.1 | NR | Earlobe, helix, and the whole pinna | Ear piercing, trauma, ear surgery | 1-15^c^ | NR
Qiao, 2017, 29798227 | Surgical excision → RT + diprosone = 40 | Corticosteroid injection locally during excision. 5 Gy per fraction, total dose of 15 Gy, post-excision. | NR | NR | 25.1 | NR | Earlobe, helix, and the whole pinna | Ear piercing, trauma, ear surgery | 1-15^c^ | NR
Sclafani, 1996, 8646474 | Surgical excision → RT = 16 | 7-10 Gy per fraction and a single dose, 3 hours post-excision. Patients were instructed to apply Bacitracin ointment to the wound three times daily for 10 days. Patients were advised not to have their ears repierced. | 28 | 28.4^a,b^ | 4 (14.3)^a^ | 1 (3.6)^a^ | Ear Lobule only = 25 (89.3)^a^;; Lobule and helix = 3 (10.7)^a^ | Piercing | 1.6^a,b^ | NR | Previous steroid or surgery, N (%): 19 (67.9)^a^
Sclafani, 1996, 8646474 | Surgical excision → Triamcinolone acetate = 12 | Intralesional injections of 0.4 cc immediately after wound closure and on days 7, 21, and 35 post-excision. Patients were instructed to apply Bacitracin ointment to the wound three times daily for 10 days. Patients were advised not to have their ears repierced. | 28 | 28.4^a,b^ | 4 (14.3)^a^ | 1 (3.6)^a^ | Ear Lobule only = 25 (89.3)^a^;; Lobule and helix = 3 (10.7)^a^ | Piercing | 1.6^a,b^ | NR | Previous steroid or surgery, N (%): 19 (67.9)^a^

Notes.

a Values calculated by the research team based on data provided in the article;

b Mean (SD);

c Range.

Abbreviations. 5-FU=5-fluorouracil; cc=cubic centimeter; cm=centimeters; Gy=gray; IQR=interquartile range; mg=milligrams; mL=milliliter; NR=not reported; PMID=PubMed ID; RT=radiation therapy.

## APPENDIX E-3 KELOIDS QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants or study personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confoundders | Other bias | Overall RoB
Akinbiyi, 2021, 3287869, NRCS | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Unclear | Yes (Low concern) | No (High concern)^a^ | No (Low concern) | High (NRCS)
Aluko-Olokun, 2014, RCT | No (Low concern) | No (High concern) | No (High concern) | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Khalid, 2018, 2953488, RCT | No (Low concern) | Yes (Low concern) | No (High concern) | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Li, 2022, 3658284, RCT | No (Low concern) | No (High concern | No (High concern) | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Qiao, 2017, 2979822, NRCS | NA | NA | NA | Unclear | No (Low concern) | NA | NA | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (High concern)^a^ | No (Low concern) | High (NRCS)
Sclafani, 1996, 8646474, RCT | Unclear | Unclear | No (High concern) | Unclear | Yes (High concern)^b^ | No (Low concern) | No (High concern)^b^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | High (RCT)

Notes.

a Crude analysis;

b 48% of patients were lost to follow-up and analysis included only those with complete follow-up.

Abbreviations. NA=not applicable; NRCS=non-randomized controlled study; RCT=randomized controlled trial.

## APPENDIX E-4 KELOIDS RESULTS SUMMARY

Author, Year, PMID | Comparison | Recurrence, Persistence, Effectiveness, or Pain | Side Effects | Cosmetic Outcomes and Skin Condition | Patient Satisfaction/Experience/QoL
Akinbiyi, 2021, 32878694 | Surgical excision → RT; vs; Surgical excision; Follow-up (mo), Median (IQR) = 15.4 months (IQR: 5.6-30.7) | Recurrence (undefined) (N=94 vs 95), [Median 15.4 mo], N (%) ^a^; 35 (37.9) vs 36 (37.2); UnadOR = (95% CI) = 1.03 (0.57, 1.85)^a^ | Complication (undefined)) (N=94 vs 95), [Median 15.4 mo], N (%) ^a^; 17 (17.9) vs 6 (6.3); UnadOR = (95% CI) = 3.88 (1.37, 11.00)^a^ | NR^b^ | NR
Aluko-Olokun, 2014 | Surgical excision → RT; vs; Triamcinolone; Follow-up (wk) = 26 | Recurrence or persistence (flattened lesion swells above invades normal skin) (N= 53 vs 54), [14-26 weeks], N (%); 22 (41.5) vs 10 (18.5); OR = (95% CI) = 3.12 (1.30, 7.51)^a^ | Complications (undefined) (N=53 vs 54), [14-26 weeks], N (%); 31 (58.5) vs 30 (55.6); OR = (95% CI) = 1.13 (0.52, 2.42)^a^ | Cosmetic Outcomes and Skin conditions (Complications) (N=53 vs 54), [14-26 weeks], N (%) ^a^; Hyperpigmentation; 6 (11.3) vs 8 (14.8); OR = (95% CI) = 0.73 (0.24, 2.28)^a^; Hypopigmentation; 0 (0.0) vs 25 (46.3); RD = (95% CI) = −0.463 (−0.596, −0.330)^a^; Skin atrophy; 0 (0.0) vs 8 (14.8); RD = (95% CI) = (95% CI) = −0.148 (−0.243, −0.053)^a^; Pruritus; 30 (56.6) vs 0 (0.0); RD = (95% CI) = 0.566 (0.431, 0.699)^a^; Tenderness; 8 (15.1) vs 0 (0.0); RD = (95% CI) = 0.151 (0.055, 0.247)^a^; Ulceration; 0 (0.0) vs 14 (25.9); RD = (95% CI) = −0.259 (−0.376,−0.142)^a^; Telangiectasia; 0 (0.0) vs 8 (14.8); RD = (95% CI) = −0.148 (−0.243, −0.053)^a^ | NR
Khalid, 2018, 29534885 | Surgical excision → RT; vs; Surgical excision → 5-FU + TAC; Follow-up (mo), Median= 19 vs 20 | Recurrence (undefined) (N=30 vs 30), [6 mo], N (%); 17 (56.7) vs 8 (26.7)^a^; OR = (95% CI)= 3.60 (1.22, 10.64)^a^ | Epidermolysis and later wound dehiscence (N=30 vs 30), N (%); 0 (0) vs 2 (6.67); RD = (95% CI)= −0.067 (−0.156, 0.023); Skin redness (N=30 vs 30), N (%); 3 (10) vs 0 (0); RD = (95% CI)= 0.100 (−0.007, 0.207)^a^ | NR | NR
Li, 2022, 36582847 | Surgical excision → RT; vs; 5-FU + betamethasone; Follow-up (mo), Median= 10 vs 9 | Recurrence (pruritus or pain increased, keloid appearing again and exceeding the original range) (N=17 vs 20), [8-12 mo], N (%); 1 (5.9) vs 4 (20.0); OR = (95% CI)= 0.25 (0.03, 2.49)^a^; Pain (POSAS-PSAS) (N=17 vs 20), [4 mo], Mean (SD); 1.7 (1.6) vs 1.7 (1.5); MD = 0.00 (−1.04, 1.04)^a^ | There was none of the malignant transformation or systemic side effects. | Cosmetic Outcomes and Skin conditions (Adverse side effects) (N=17 vs 20), [4 mo], N (%) ^a^; Hyperpigmentation; 5 (29.4) vs 1 (5.0); OR = (95% CI) = 7.92 (0.82, 76.28)^a^; Hypopigmentation; 0 (0.0) vs 0 (0.0); Scab; 1 (5.9) vs 3 (15.0); OR = (95% CI) = 0.35 (0.03, 3.77)^a^; Telangiectasia; 4 (23.5) vs 1 (5.0); OR = (95% CI) = 5.58 (0.58, 58.43)^a^; Appearance (VSS), Mean (SD); 4.24 (1.48) vs 6.10 (1.17); MD = −1.86 (−2.75, −0.98)^a^; Pruritus (POSAS-PSAS), Mean (SD); 2.3 (2.4) vs 2.08 (1.39); MD = (95%CI) = 0.22 (−1.07, 1.51)^a^; POSAS-OSAS (N=17 vs 20), [4 mo], Mean (SD); 18.53 (6.15) vs 23.35 (3.95); MD = −4.82 (−8.22, −1.42)^a^; POSAS-PSAS (N= 17 vs 20), [4 mo], Mean (SD); 16.83 (4.45) vs 28.8 (7.38); MD = −11.75 (−15.9, −17.59)^a^
| Surgical excision → RT; vs; Surgical excision → 5-FU + betamethasone; Follow-up (mo), Median= 10 vs 9 | Recurrence (pruritus or pain increased, keloid appearing again and exceeding the original range) (N=17 vs 18), [8-12 mo], N (%); 1 (5.9) vs 2 (11.1); OR = (95% CI) = 0.50 (0.04, 6.08)^a^; Pain (POSAS-PSAS) (N=17 vs 18), [4 mo], Mean (SD); 1.7±1.6 vs 1.3±0.8; MD = 0.4 (−0.46, 1.26)^a^ | There was none of the malignant transformation or systemic side effects. | Cosmetic Outcomes and Skin conditions (Adverse side effects) (N=17 vs 18), [4 mo], N (%) ^a^; Hyperpigmentation; 5 (29.4) vs 2 (11.1); OR = (95% CI) = 3.33 (0.55, 20.22)^a^; Hypopigmentation; 0 (0.0) vs 1 (5.6); RD = (95% CI) = −0.056 (−0.161, 0.050)^a^; Scab; 1 (5.9) vs 3 (16.7); OR = (95% CI) = 0.31 (0.03, 3.34)^a^; Telangiectasia; 4 (23.5) vs 2 (11.1); OR = (95% CI) = 2.46 (0.39, 15.63)^a^; Appearance (VSS), Mean (SD); 4.24 (1.48) vs 4.56 (2.06),; MD = −0.32 (−1.56, 0.92)^a^; Pruritus (PSAS), Mean (SD); 2.3 (2.4) vs 2.1 (1.8); MD = (95%CI) = 0.2 (−1.25, 1.65)^a^; POSAS-OSAS (N=17 vs 18), [4 mo], Mean (SD); 18.53 (6.15) vs 18.5 (6.12),; MD = 0.03 (−4.19, 4.25); POSAS-PSAS (N=17 vs 18), [4 mo], Mean (SD); 16.83 (4.45) vs 20.7 (7.6); MD = −3.87 (−8.19, 0.45)^a^
Qiao, 2017, 29798227 | Surgical excision → RT; vs; Surgical excision; Follow-up (mo) = 12 | Ineffectiveness (Dariz Criteria) (N=40 vs 40), N (%); 7 (17.5) vs 19 (47.5)^a^; UnadOR = (95% CI) = 0.23 (0.08, 0.65)^a^ | NR | NR | -
Qiao, 2017, 29798227 | Surgical excision → RT; vs; Surgical excision → corticoid; Follow-up (mo) = 12 | Ineffectiveness (Dariz Criteria) (N=40 vs 40), N (%); 7 (17.5) vs 8 (20.0)^a^; UnadOR = (95% CI) = 0.85 (0.28, 2.61)^a^ | NR | NR
Qiao, 2017, 29798227 | Surgical excision → RT; vs; Surgical excision → RT + corticoid; Follow-up (mo) = 12 | Ineffectiveness (Dariz Criteria) (N=40 vs 40), N (%); 7 (17.5) vs 1 (2.5)^a^; UnadOR = (95% CI) = 8.27 (0.97, 70.74)^a^ | NR | NR
Sclafani, 1996, 8646474 | Surgical excision → RT; vs; Surgical excision → Triamcinolone; Follow-up (mo), Median = 18 | Recurrence (Any visible or palpable nodularity to the scar) (N=16 vs 12), [Median 18 mo], N (%); 2 (12.5) vs 4 (33.0); OR = (95% CI) = 0.29 (0.04, 1.92)^a^ | NR | NR | -

Notes.

a Values calculated by the research team based on data provided in the article;

b Data were only available for the medical management arm so were not extracted.

Abbreviations. 5-FU=5-fluorouracil; CI=confidence interval; Gy=gray; IQR=interquartile range; mo=months; NR=not reported; POSAS=Patient and Observer Assessment Scale; PSAS=patient assessment scale; QoL=quality of life; RT=radiation therapy; SD=standard deviation; TAC=triamcinolone acetonide; OSAS=observer assessment scale; UnadMD=unadjusted mean difference; UnadOR=unadjusted odds ratio; UnadRD=unadjusted risk difference; VSS=Vancouver Scar Scale.