# APPENDIX D HETEROTOPIC OSSIFICATION

## APPENDIX D-1 HETEROTOPIC OSSIFICATION DESIGN DETAILS

Author, Year, PMID, Protocol Number, Country | Study Design | Study Dates | Study Location Details (Hospital Type, Centers) | Intent of RT | Inclusion Criteria | Exclusion Criteria
Bremen-Kühne, 1997, 9446435, Germany | RCT | 1992 - 1994 | Other/unclear, Single center | Prevention of emergence | Patients at risk for HO after hip joint replacement surgery with cementless, ceramic-coated prostheses. Age 40 years or older. | Patients with contraindications for NSAIDs or radiation (including hematologic disease, ulcers, asthma and allergies, cardiac disease, neoplasms)
Burd, 2003, 12892193, USA | RCT | 1992 - 2001 | Teaching hospital, Single center | Prevention of emergence | Patients at risk for HO for using a posterior or extensile surgical approach or anterior surgical approach and appeared to be limited to with concomitant fractures of the femur, tibia, humerus, and/or forearm. | NR
Hamid, 2010, 20810853, USA | RCT | 2005 - 2008 | Other/unclear, Multicenter | Prevention of emergence | NR | Having associated injury of head, burns of >20% of the body surface area or involving the operative site, or a spinal cord injury affecting the upper extremity’s function. Open fractures that could not be closed within 72 hours of the initial surgery.
Ince, 2007, 17415004, Germany | RCT and historical control | 1988 | Teaching hospital, Single center | Prevention of emergence | Availability of at least 4 consecutive pelvic radiographs. | NR
Kienapfel, 1999, 10447627, Germany | RCT | 1992 - 1993 | Teaching hospital, Single center | Prevention of emergence | Primary osteoarthritis, rheumatoid arthritis, secondary osteoarthritis due to congenital hip dysplasia or avascular necrosis of the femoral head and femoral neck fractures. | Idiopathic skeletal hyperostosis, ankylosing spondylitis, Paget’s disease, acetabular or femoral stem fractures and total hip revision procedures.
Kölbl, 1997, 9392532, Germany | RCT and historical control | 1993 - 1994 | Other/unclear, NR/unclear | Prevention of emergence | NR | NR
Kölbl, 1998, 9788422, Germany | RCT and historical control | 1995 - 1996 | Other/unclear, NR/unclear | Prevention of emergence | Total hip replacement operated because of degenerative diseases, and the risk for development of HO was low or medium. | Patients with known gastric ulcer.
Leeuwen, 1998, 9602765, Netherlands | RCT | 1989 - 1992 | NR/ynclear, Other/unclear | Prevention of emergence | Patients who did not use NSAIDs and were considered to be at risk for the development of ectopic bone. | NR
Moore, 1998, 9546456, USA | RCT | 1993 - 1996 | Teaching hospital, Single center | Prevention of emergence | Patients who required either a Kocher-Langenbeck, a combined anterior and posterior approach, or an extended iliofemoral approach for the fixation of an acetabular fracture. | Those with a history of allergy to indomethacin, an active peptic ulcer or who could not be transported for radiation.
Sell, 1998, 9880175, Germany | RCT | 1992 - 1993 | Teaching hospital, Single center | Primary treatment/prevention of recurrence; Prevention of emergence | NR | Any other prophylactic procedure for periarticular ossifications was excluded. Participants younger than 45 years of age and those with a previous irradiation of the extremity. Severe gastrointestinal problems (eg, gastrointestinal bleeding, severe ulcer) in the past were a contraindication for NSAID.

Abbreviations. HO=heterotopic ossification; NR=not reported; NSAIDs=non-steroid anti-inflammatory; PMID=PubMed ID; RCT=randomized controlled trial; RT=radiation therapy.

## APPENDIX D-2 HETEROTOPIC OSSIFICATION BASELINE DATA

Author, Year, PMID | N Patients | Intervention | Age | % Male | % White | Location | HO History | Other
Bremen-Kühne, 1997, 9446435, Germany^a^ | Surgery →RT = 35 (19 assessed) | THA followed by 6 Gy within 4 days | NR | 38 (56) | NR | Hip | NR
Bremen-Kühne, 1997, 9446435, Germany^a^ | Surgery →Indomethacin = 33 | THA followed by 100 mg once, then 25 mg 3 times daily, for 10 days | NR | 38 (56) | NR | Hip | NR
Burd, 2003, 12892193, USA | Surgery →RT = 74 | ORIF followed by 8 Gy 72 hours. | 38.6^b^ | NR | NR | Humerus forearm; Femur tibia/fibula | NR | Acetabular fracture, N (%) = 112 (100)
Burd, 2003, 12892193, USA | Surgery →Indomethacin = 38 | ORIF followed by 2 5mg 3 times daily, for 6 weeks. | 38.6^b^ | NR | NR | Humerus forearm; Femur tibia/fibula | NR | Acetabular fracture, N (%) = 112 (100)
Hamid, 2010, 20810853, USA | Surgery →RT = 21 | Fracture fixation followed by 7 Gy 72 hours. | 44.3 (16.4)^b,c^ | 24 (55.6)^c^ | NR | Elbow, humerus | NR | Open fracture (N=45), N (%) = 24 (53.3)^c^; Fracture type (N=45), N (%); Patrial articular arcature = 16 (35.6)^c^; Complete articular involvement = 29 (64.4)^c^; All patients sustained [an intraarticular distal humeral fracture or a fracture-dislocation of the elbow with proximal radial and/or ulnar fracture]
Hamid, 2010, 20810853, USA | Surgery = 24 | Fracture fixation with no prophylaxis. | 44.3 (16.4)^b,c^ | 24 (55.6)^c^ | NR | Elbow, humerus | NR
Ince, 2007, 17415004, Germany | Surgery →RT = 106 | THA followed by 4 doses of 3 Gy at 2-day intervals beginning no later than the fifth postoperative da, total dose of 12Gy | 63.9 (11.3)^b,c^ | 146 (51.0)^c^ | NR | Hip | NR | Initial diagnosis (N=286), N (%)^c,d^; Osteoarthritis = 246 (86.0); Avascular osteonecrosis= 22 (7.7); Fracture= 6 (2.1); Developmental dysplasia of the hip= 13 (4.5)
Ince, 2007, 17415004, Germany | Surgery →Indomethacin = 98 | THA followed by 2×50 mg per day with mucoprotection for 14 days beginning on the first postoperative day. | 63.9 (11.3)^b,c^ | 146 (51.0)^c^ | NR | Hip | NR | Initial diagnosis (N=286), N (%)^c,d^; Osteoarthritis = 246 (86.0); Avascular osteonecrosis= 22 (7.7); Fracture= 6 (2.1); Developmental dysplasia of the hip= 13 (4.5)
Ince, 2007, 17415004, Germany | Surgery →Analgesia (historical control) = 82 | THA followed by paracetamol, metamizole, and opioids. | 63.9 (11.3)^b,c^ | 146 (51.0)^c^ | NR | Hip | NR | Initial diagnosis (N=286), N (%)^c,d^; Osteoarthritis = 246 (86.0); Avascular osteonecrosis= 22 (7.7); Fracture= 6 (2.1); Developmental dysplasia of the hip= 13 (4.5)
Kienapfel, 1999, 10447627, Germany | Surgery →RT = 49 | THA followed by a single dose of 6 Gy 48-96 hours post-surgery. | 64.7 (33-86)^c^ | 57 (37.0)^c^ | NR | Hip | NR
Kienapfel, 1999, 10447627, Germany | Surgery →Indomethacin = 55 | THA followed 50 mg twice a day for 42 days, post-surgery. All patients with a history of peptic ulcer, gastroduodenal haemorrhage or gastritis and those who developed dyspepsia during indomethacin medication were additionally medicated with the H2-receptor antagonist cimetidine 200 mg | 64.7 (33-86)^c^ | 57 (37.0)^c^ | NR | Hip | NR
Kienapfel, 1999, 10447627, Germany | Surgery = 50 | Surgery with no prophylaxis. | 64.7 (33-86)^c^ | 57 (37.0)^c^ | NR | Hip | NR
Kölbl, 1997, 9392532, Germany | Surgery →RT-5Gy = 93 | THR followed by a single dose of 5 Gy within 4 days. | 65.9^b^ | 142 (35.4)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 77 (19.2)^c^ | Most patients were operated because of degenerative diseases.
Kölbl, 1997, 9392532, Germany | Surgery →RT-7Gy = 95 | THR followed by a single dose of 7 Gy within 4 days. | 65.9^b^ | 142 (35.4)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 77 (19.2)^c^ | Most patients were operated because of degenerative diseases.
Kölbl, 1997, 9392532, Germany | Surgery → Indomethacin = 113 | THR followed 2×50 mg for 7 days. | 65.9^b^ | 142 (35.4)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 77 (19.2)^c^ | Most patients were operated because of degenerative diseases.
Kölbl, 1997, 9392532, Germany | Surgery (historical control) = 100 | THR with no prophylaxis. | 65.9^b^ | 142 (35.4)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 77 (19.2)^c^ | Most patients were operated because of degenerative diseases.
Kölbl, 1998, 9788422, Germany | RT →Surgery = 46 | 7 Gy 16-20 hours pre-surgery followed by THR. | 65.0^b,c^ | 81 (40.5)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 27 (13.5)^c^ | Most patients were operated because of degenerative diseases
Kölbl, 1998, 9788422, Germany | Surgery →Voltaren = 54 | THR followed by 2×75 mg for 14 days with medicamentous protection of gastric mucosa, started at the first postoperative day | 65.0^b,c^ | 81 (40.5)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 27 (13.5)^c^ | Most patients were operated because of degenerative diseases
Kölbl, 1998, 9788422, Germany | Surgery (historical control) = 100 | THR with no prophylaxis. | 65.0^b,c^ | 81 (40.5)^c^ | NR | Hip | Previous Brooker score 1-4, N (%)= 27 (13.5)^c^ | Most patients were operated because of degenerative diseases
Leeuwen, 2009, 9602765, Netherlands | RT →Surgery = 41 | 5 Gy 24 hours pre-surgery followed by THA. | 65.5 (24-80)^c,e^ | 17 (29.8)^c^ | NR | Hip | NR
Leeuwen, 2009, 9602765, Netherlands | Surgery = 16 | THA with no prophylaxis. | 65.5 (24-80)^c,e^ | 17 (29.8)^c^ | NR | Hip | NR
Moore, 1998, 9546456, USA | Surgery →RT = 33 | Acetabular fracture fixation followed by single dose of 8 Gy within48 hours post-surgery | 45.0 (18-87)^c,e^ | 52 (69.3) | NR | Hip | NR
Moore, 1998, 9546456, USA | Surgery →Indomethacin = 39 | Acetabular fracture fixation; 25 mg 24 hours pre-surgery and 25 mg daily, for 6 weeks post-surgery. | 45.0 (18-87)^c,e^ | 52 (69.3) | NR | Hip | NR
Sell, 1998, 9880175, Germany | Surgery →RT = 76 | THR followed by 3.3 Gy per fraction, total dose of 9.9 Gy completed within 8 days post-surgery. | 60.8 (36-82)^c,e^ | 89 (58.2)^c^ | NR | Hip | Brooker 1, n=1; Contralaterally; Brooker 1, n=2; Brooker 2, n=1
Sell, 1998, 9880175, Germany | Surgery →diclofenac= 77 | THR followed by 3×50 mg. over a period of 3 weeks. | 60.8 (36-82)^c,e^ | 89 (58.2)^c^ | NR | Hip | Brooker 1, n=1; Contralaterally; Brooker 1, n=2; Brooker 2, n=1

Notes.

a This study only reported per protocol data;

b Mean (SD);

c Values calculated by the research team based on data provided in the article;

d Numbers are estimated based on data provided in the study;

e Mean (range).

Abbreviations. Gy=gray; HO=heterotopic ossification; mg=milligrams; NR=not reported; NSAIDs=non-steroidal anti-inflammatory; ORIF=open reduction and internal fixation; PMID=PubMed ID; RT=radiation therapy; THA=total hip arthroplasty; THR=total hip replacement.

## APPENDIX D-3 HETEROTOPIC OSSIFICATION QUALITY RATING

Author, Year, PMID, Design | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessor | Incomplete outcome data | Selective reporting | Intention-to-treat analysis | Clear reporting | Clear eligibility criteria | Interventions adequately described | Outcomes fully defined | Representativeness of the cohort | Comparator representativeness | Adjustment for confounders | Other bias | Overall RoB
Bremen-Kühne, 1997, 9446435 RCT | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | No (Low concern) | No (High concern)^a^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | Yes (High concern)^b^ | High (RCT)
Burd, 2003, 1289219, RCT | Unclear | Unclear | Yes (Low concern) | Yes (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Hamid, 2010, 2081085, RCT | Yes (Low concern) | Yes (Low concern) | Unclear | Yes (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Ince, 2007, 17415004, RCT | Yes (Low concern) | Unclear | Yes (Low concern) | Yes (Low concern) | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Kienapfel, 1999, 10447627, RCT | Unclear | Unclear | Unclear | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Kölbl, 1997, 9392532, RCT | Unclear | Unclear | Unclear | Unclear | Unclear | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)
Kölbl, 1998, 9788422, RCT | Yes (Low concern) | Yes (Low concern) | Unclear | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern | Yes (Low concern | Yes (Low concern | Yes (Low concern | NA | NA | NA | No (Low concern) | Medium (RCT)
Leeuwen, 1998, 9602765, RCT | Yes (Low concern) | Yes (Low concern) | Unclear | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern | Yes (Low concern | Yes (Low concern | Yes (Low concern | NA | NA | NA | Yes (High concern)^c^ | Medium (RCT)
Moore, 1998, 9546456, RCT | Yes (Low concern) | Unclear | No (High concern) | Yes (Low concern) | No (Low concern) | No (Low concern) | Unclear | Yes (Low concern | Yes (Low concern | Yes (Low concern | Yes (Low concern | NA | NA | NA | No (Low concern) | Medium (RCT)
Sell, 1998, 9880175, RCT | Yes (Low concern) | Unclear | No (High concern) | Unclear | No (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | NA | NA | NA | No (Low concern) | Medium (RCT)

Notes.

a No intention to treat results;

b Only 19 out of 35 patients in the RT arm versus 31 out of 33 patients in the indomethacin arm were analyzed;

c Unclear why patients were randomized unevenly to different treatment arms.

Abbreviations. NA=not applicable; RCT=randomized controlled trial.

## APPENDIX D-4 HETEROTOPIC OSSIFICATION RESULTS SUMMARY

Author, Year, PMID | Comparison | Heterotopic Ossification at Follow-Up | Function and Pain | Side Effects | Patient Satisfaction/Experience/QoL
Bremen-Kühne, 1997, 9446435, Germany | Surgery → RT; vs; Surgery → Indomethacin; Follow-up (mo) = 6-12 | HO grade I or II Brooker classification (N = 19 vs 31), N(%)^a^,^b^; 6 months; 9 (47.4) vs 10 (32.3); OR = 1.89 (0.58, 6.11)^b^; 12 months; 9 (47.4) vs 10 (32.3); OR = 1.89 (0.58, 6.11)^b^; HO grade III Brooker classification (N = 19 vs 31), [12 months], N (%)^a,b^; 0 (0) vs 1 (3.2); RD = −0.32 (−0.094, 0.030)^b^; No grade IV in per protocol analysis | Merle d’Aubigne (pain Score) was assessed but no comparisons extractable^a^ | NR | Self-assessment of outcome as “good” or “very good” (N = 19 vs 31), N(%)^a,b^; Discharge; 17 (89.5) vs 28 (90.3); OR = 0.91 (0.14, 6.02)^b^; 12 months; 15 (80.0) vs 27 (87.1); OR = 0.56 (0.12, 2.55)^b^
Burd, 2003, 12892193, USA | Surgery → RT; vs; Surgery → Indomethacin; Follow-up (mo), Mean = 5.3 | Radiologic failure (fracture nonunion) (N= 74 vs 38 patients), [mean 5.3 mo], N (%)^b^; 5 (6.8) vs 11 (28.9); OR = 0.18 (0.06, 0.56)^b^ | | | NR
Hamid, 2010, 20810853, USA | Surgery → RT; vs; Surgery; Follow-up (mo), Mean = 7.5 | Incidence of HO (N= 21 vs 24), [mean 7.5 mo], N (%)^b^; 7 (33.0) vs 13 (54.0); OR = 0.42 (0.13, 1.42)^b^; Grade III-IV HO (Brooker classification) (N= 21 vs 24), [mean 7.5 mo], N (%))^b^; 2 (9.5) vs 4 (16.7); OR = 0.53 (0.09, 3.22)^b^; Radiologic failure (fracture nonunion) (N= 21 vs 24), [mean 7.5 mo], N (%)^b^; 8 (38.1) vs 1 (4.2); OR = 14.15 (1.59, 126.13)^b^; Return to operating room for heterotopic ossification excision (N = 21 vs 24), N (%)^b^; 0 (0) vs 3 (12); RD = −0.125 (−0.257, 0.007)^b^ | MEPS (points out of scale of 100)^c^, [mean 7.5mo]; 69 vs 66, p = 0.6; Mean elbow flexion, [mean 7.5 mo]; 116° vs 113°, p = 0.53; Mean elbow extension, [mean 7.5 mo]; 29° vs 22°, p = 0.18; Mean pronation, [mean 7.5 mo]; 71° vs 69°, p = 0.8; Mean supination, [mean 7.5 mo]; 70° vs 64°, p = 0.54 | Post-operative infection (N=21 vs 24), [mean 7.5 mo], N (%)^b^; 2 (9.5) vs 2 (8.3); OR = 1.16 (0.15, 9.03)^b^; Manipulation (not defined) (N= 21 vs 24), [mean 7.5 mo], N (%)^b^; 0 (0) vs 3 (12); RD = −0.125 (−0.257, 0.007)^b^ | NR
Ince, 2007, 17415004, Germany | Surgery → RT; vs; Surgery → Indomethacin; Follow-up (mo), Mean = 56.5^b^ | Incidence of HO (Brooker Classification), (N=106 vs 98), [2y], N (%)^b^; HO grade 1; 5 (5.0) vs 9 (8.9); OR = 0.49 (0.16, 1.52)^b^; HO grade 2; 0 (0.0) vs 2 (2.2); RD = −0.020 (−0.048, 0.008)^b^; HO grade 3; 0 (0.0) vs 1 (1.1); RD = −0.010 (−0.030, 0.010)^b^; HO grade 4; Zero events in both arms; HO grade 1-4; 5 (5.0) vs 12 (12.2); OR = 0.35 (0.12, 1.05)^b^ | Harris Hip Score [5y], Mean (SD); 86.2 (12.5) vs 87.1 (10.8); MD −0.90 (−4.14, 2.34)^b^ | Number of Implants that migrated greater than 1 mm, N (%)^b^; 2 year follow-up (N=106 vs 98); 7 (6.6) vs 8 (8.1); OR = 0.08 (0.28, 2.28)^b^; 5 year follow-up (N=46 vs 49),; 3 (6.5) vs 4 (8.2); OR = 0.78 (0.17, 3.71)^b^; Radiolucent lines greater than 1 mm (5 years), N; 0 vs 4; No patient underwent hip revision surgery; No acetabular component was considered loose
Ince, 2007, 17415004, Germany | Surgery → RT; vs; Surgery → Non-NSAID Analgesia (historical control); Follow-up (mo), Mean = 59.0^b^ | Incidence of HO (Brooker Classification), (N=106 vs 82), [2y], N (%)^b^; HO grade 1; 5 (5.0) vs 21 (26.0); OR = 0.14 (0.05, 0.40)^b^; HO grade 2; 0 (0.0) vs 3 (15.0); RD = −0.037 (−0.077, 0.004)^b^; HO grade 3; 0 (0.0) vs 16 (19.0); RD = −0.195 (−0.281, −0.109)^b^; HO grade 4; 0 (0.0) vs 4 (5.0); RD = −0.049 (−0.095, −0.002)^b^; HO grade 1-4; 5 (5.0) vs 53 (65.0); OR = 0.03 (0.01, 0.07)^b^ | Harris Hip Score [5y], mean (SD); 86.2 (12.5) vs 87.0 (10.0); MD = −0.80 (−4.13, 2.53)^b^ | Number of implants that migrated greater than 1 mm, N(%)^b^; 2 year follow-up (N= 106 vs 82); 7 (6.6) vs 4 (4.9); OR = 1.38 (0.39, 4.88)^b^; 5 year follow-up (N= 46 vs 61); 3 (6.5) vs 5 (8.2); OR = 0.78 (0.18, 3.45)^b^; Radiolucent lines greater than 1 mm (5 y), N; 0 vs 7; No patient underwent hip revision surgery; No acetabular component was considered loose
Kienapfel, 1999, 10447627, Germany | Surgery → RT; vs; Surgery; Follow-up (mo) = 18 | Incidence of HO (Brooker Classification), (N= 49 vs 50), [18mo], N (%)^b^; HO grade 1; 10 (20.4) vs 8 (16.0); OR = 1.35 (0.48, 3.76)^b^; HO grade 2; 2 (4.1) vs 9 (18.0); OR = 0.19 (0.04, 0.95)^b^; HO grade 3; 0 (0.0) vs 11 (22.0); RD = −0.220 (−0.335, −0.105)^b^; HO grade 4; 0 (0.0) vs 2 (4.0); RD = −0.040 (−0.094, 0.014)^b^; HO grade 1-4; 12 (24.5) vs 30 (60.0); OR = 0.22 (0.09, 0.51)^b^ | Harris Hip Score [18 mo], Mean (range); 86.4 (67-100) vs 81.7 (47-97), p-value = NS; PAHHS [18 mo], Mean (range); 68.8 (53-80) vs 64.7 (36-77), p-value = NS; IAHHS [18 mo], Mean (range); 17.5 (12-20) vs 16.9 (10-20), p-value = NS | Prolonged (>5 days) wound secretion, [18 mo], N (%)^b^; 6 (12.2) vs 1 (2.0); OR = 6.84 (0.79, 59.07)^b^; Wound dehiscence, [18mo], N (%)^b^; 1 (2.0) vs 1 (2.0); OR = 1.02 (0.06, 16.79)^b^; Deep vein thrombosis [18mo], N (%)^b^; 3 (6.1) vs 3 (6.0); OR = 1.02 (0.20, 5.33)^b^; Dyspepsia [18mo], N (%)^b^; 4 (8.2) vs 5 (10.0); OR = 0.80 (0.20, 3.17)^b^; At the time of the last follow-up, none of the arthroplasties had failed, and no revision surgery had been necessary. | NR
Kienapfel, 1999, 10447627, Germany | Surgery → RT; vs; Surgery → Indomethacin; Follow-up (mo) = 18 | Incidence of HO (Brooker Classification), (N=49 vs 55), [18 mo], N (%)^b^; HO grade 1; 10 (20.4) vs 17 (30.9); OR = 0.57 (0.23, 1.41)^b^; HO grade 2; 2 (4.1) vs 3 (5.5); OR = 0.74 (0.12, 4.61)^b^; HO grade 3 and 4; Zero events in both arms; HO grade 1-4; 12 (24.5) vs 20 (36.4); OR = 0.57 (0.24, 1.33)^b^ | Harris Hip Score, Mean (range); 86.4 (67-100) vs 85.0 (63-100), p-value = NS; PAHHS, Mean (range); 68.8 (53-80) vs 67.6 (47-80), p-value = NS; IAHHS, Mean (range); 17.5 (12-20) vs 17.1 (12-20), p-value = NS | Prolonged (>5 days) wound secretion [18mo], N (%)^b^; 6 (12.2) vs 0 (0.0); RD = 0.122 (0.031, 0.214)^b^; Wound dehiscence [18mo], N (%)^b^; 1 (2.0) vs 2 (4.0); OR = 0.55 (0.05, 6.28)^b^; Deep vein thrombosis [18mo], N (%)^b^; 3 (6.1) vs 4 (8.0); OR = 0.83 (0.18, 3.91)^b^; Dyspepsia [18mo], N (%)^b^; 4 (8.2) vs 15 (30.0); OR = 0.24 (0.07, 0.77)^b^; At the time of the last follow-up, none of the arthroplasties had failed, and no revision surgery had been necessary. | NR
Kölbl, 1997, 9392532, Germany | Surgery → RT-5; vs; Surgery → Indomethacin; Follow-up (mo) = 0-12 | Incidence of HO (Brooker Classification), (N= 93 vs 113), [3-12 mo], N (%)^b^; HO grade 1; 23 (24.7) vs 9 (8.0); OR = 3.80 (1.66, 8.69)^b^; HO grade 2; 4 (4.3) vs 7 (6.2); OR = 0.68 (0.19, 2.40)^b^; HO grade 3; 1 (1.1) vs 2 (1.7); OR = 0.60 (0.05, 6.76)^b^; HO grade 4; Zero events in both arms.; HO grade 1-4; 28 (30.1) vs 18 (15.9); OR = 2.27 (1.16, 4.45)^b^ | | NR | NR
Kölbl, 1997, 9392532, Germany | Surgery → RT-5; vs; Surgery (historical control); Follow-up = Immediately after, 3, and 12 mo post-therapy | Incidence of HO (Brooker Classification), (N= 93 vs 100), [3-12 mo], N (%)^b^; HO grade 1; 23 (24.7) vs 26 (26.0); OR = 0.94 (0.49, 1.79)^b^; HO grade 2; 4 (4.3) vs 15 (15.0); OR = 0.25 (0.08, 0.80)^b^; HO grade 3; 1 (1.1) vs 19 (19.0); OR = 0.05 (0.01, 0.35)^b^; HO grade 4; 0 (0.0) vs 5 (5.0); RD = −0.050 (−0.093, −0.007)^b^; HO grade 1-4; 28 (30.1) vs 65 (65.0); OR = 0.23 (0.13, 0.42)^b^ | | NR | NR
Kölbl, 1997, 9392532, Germany | Surgery → RT-7; vs; Surgery → Indomethacin; Follow-up = Immediately after, 3, and 12 mo post-therapy | Incidence of HO (Brooker Classification), (N=95 vs 113), [3-12 mo], N (%)^b^; HO grade 1; 11 (11.6) vs 9 (8.0); OR = 1.51 (0.60, 3.82)^b^; HO grade 2; 0 (0.0) vs 7 (6.2); RD = −0.062 (−0.106, −0.018)^b^; HO grade 3; 0 (0.0) vs 2 (1.7); RD = −0.018 (−0.042, 0.007)^b^; HO grade 4; Zero events in both arms.; HO grade 1-4; 11 (11.6) vs 18 (15.9); OR = 0.69 (0.31, 1.55)^b^ | | NR | NR
Kölbl, 1997, 9392532, Germany | Surgery → RT-7; vs; Surgery (historical control); Follow-up= Immediately after, 3, and 12 mo post-therapy | Incidence of HO (Brooker Classification), (N=95 vs 100), [3-12 mo], N (%)^b^; HO grade 1; 11 (11.6) vs 26 (26.0); OR = 0.37 (0.17, 0.81)^b^; HO grade 2; 0 (0.0) vs 15 (15.0); RD = −0.150 (−0.220, −0.080)^b^; HO grade 3; 0 (0.0) vs 19 (19.0); RD = −0.190 (−0.267, −0.113)^b^; HO grade 4; 0 (0.0) vs 5 (5.0); RD = −0.050 (−0.093, −0.007)^b^; HO grade 1-4; 11 (11.6) vs 65 (65.0); OR = 0.07 (0.03, 0.15)^b^ | | NR | NR
Kölbl, 1998, 9788422, Germany | RT → Surgery; vs; Surgery → Voltaren; Follow-up= Immediately after, 3, and 6 mo post-therapy | Incidence of HO (Brooker Classification), (N=46 vs 54), [3-6 mo], N (%); HO grade 1; 17 (36.9) vs 5 (9.3); OR = 5.74 (1.92, 17.22); HO grade 2; 4 (8.7) vs 1 (1.8); OR = 0.42 (0.12, 1.44); HO grade 3; 1 (2.2) vs 0 (0.0); RD = 0.022 (−0.020, 0.064); HO grade 4; Zero events in both arms.; HO grade 1-4; 22 (47.8) vs 6 (11.1); OR = 7.33 (2.63, 20.48) | | Gastrointestinal side effects (not specified) leading to termination of therapy, N (%); 0 (0) vs 3 (5.6); RD = −0.056 (−0.117, 0.006) | NR
Kölbl, 1998, 9788422, Germany | RT → Surgery; vs; Surgery (historical control); Follow-up = Immediately after, 3, and 6 mo post-therapy | Incidence of HO (Brooker Classification), (N=46 vs 100), [3-6 mo], N (%)^b^; HO grade 1; 17 (36.9) vs 26 (26.0); OR = 1.67 (0.79, 3.52)^b^; HO grade 2; 4 (8.7) vs 15 (15.0); OR = 0.54 (0.17, 1.73)^b^; HO grade 3; 1 (2.2) vs 19 (19.0); OR = 0.09 (0.01, 0.73)^b^; HO grade 4; 0 (0.0) vs 5 (5.0); RD = −0.050 (−0.093, −0.007)^b^; HO grade 1-4; 22 (47.8) vs 65 (65.0); OR = 0.49 (0.24, 1.00) | | | NR
Leeuwen, 2009, 9602765, Netherlands | RT → Surgery; vs; Surgery; Follow-up (mo), Mean (range)= 31 (19-62) | Prevalence of HO (Brooker Classification), (N=43 vs 19), [mean ≈31mo], N (%)^b^; HO grade 1; 5 (11.6) vs 4 (21.1); OR = 0.49 (0.12, 2.09)^b^; HO grade 2; 0 (0.0) vs 4 (21.1); RD = −0.211 (−0.394, −0.027)^b^; HO grade 3; 1 (2.3) vs 5 (26.3); OR = 0.07 (0.01, 0.62)^b^; HO grade 4; 0 (0.0) vs 3 (15.8); RD = −0.158 (−0.322, 0.006)^b^; HO grade 1-4; 6 (14.0) vs 16 (84.2); OR = 0.03 (0.01, 0.14)^b^ | | One patient in the radiation group had a superficial wound infection. No other side effects reported.
Moore, 1998, 9546456, USA | Surgery → RT; vs; Surgery → Indomethacin; Follow-up (mo), Mean (range) = 11.9^b^ (6-48) | Incidence of HO (Brooker Classification) (N= 34 vs 41), [6-48mo], N (%)^b^; HO grade 1; 4 (12.1) vs 5 (12.8); OR = 0.94 (0.23, 3.82)^b^; HO grade 2; 2 (6.1) vs 6 (15.4); OR = 0.35 (0.07, 1.89)^b^; HO grade 3; 3 (9.1) vs 5 (12.8); OR = 0.68 (0.15, 3.09)^b^; HO grade 4; 0 (0.0) vs 2 (5.1); RD = −0.049 (−0.115, 0.017)^b^; HO grade 1-4; 9 (27.3) vs 18 (46.2); OR = 0.44 (0.16, 1.18)^b^ | | NR | NR
Sell, 1998, 9880175, Germany | Surgery → RT; vs; Surgery → diclofenac; Follow-up (mo) = 0.5, 3, and 6 | Incidence of HO (Brooker Classification), (N=76 vs 77), [6mo], N (%)^b^; HO grade 1; 2 (2.6) vs 16 (20.8); OR = 0.10 (0.02, 0.47)^b^; HO grade 2; 0 (0.0) vs 2 (2.6); RD = −0.026 (−0.062, 0.010)^b^; HO grade 3 and 4; Zero events in both arms; HO grade 1-4 (Brooker Classification); [6mo]; 2 (2.6) vs 18 (23.4); OR = 0.09 (0.02, 0.40)^b^ | | Reddening of wound [time not specified], N (%)^b^; 3 (3.9) vs 1 (1.3); OR = 3.12 (0.32, 30.72)^b^; Hematoma formation [time not specified], N (%)^b^; 6 (7.9) vs 7 (9.1); OR = 0.86 (0.27, 2.68)^b^; Staphylococcus epidermidis infection necessitating fistula revision [time not specified], N (%)^b^; 1 (1.3) vs 0 (0); RD = 0.013 (−0.012, 0.039)^b^; Wound dehiscence [time not specified], N (%)^b^; 9 (11.8) vs 5 (6.5); OR = 1.93 (0.62, 6.06)^b^; Gastrointestinal side effects (not specified) after the first week that caused discontinuation of treatment, N (%)^b^; 0 (0) vs 11 (14.3); RD = −0.143 (−0.221, −0.065)^b^; There was no evidence of loosening of the prosthesis in any patient.; There was no evidence that radiation had caused any negative side effects in the region of the femoral component or the acetabulum. | NR

Notes.

a Per protocol analysis;

b Values calculated by the research team based on data provided in the article;

c Mayo Elbow Performance Score (MEPS). This outcome tool is based on a 100-point scale, which measures pain (45 points), stability (10 points), function (25 points), and motion (20 points).

Abbreviation. HO=heterotopic ossification; IAHHS=investigator-assessed Harris Hip Score; MD=mean difference; MEPS=Mayo Elbow Performance Score; mm=millimeter; NR=not reported; mo=months; NSAID=non-steroidal anti-inflammatory; OR=odds ratio; PAHHS=patient-assessed Harris Hip Score; PMID=PubMed ID; QoL=quality of life; RT=radiation therapy; SD=standard deviation; unadOR=unadjusted odds ratio; unadRD=unadjusted risk difference; y=years.