# APPENDIX C CRITERIA USED IN QUALITY ASSESSMENTS

## APPENDIX C-1 COCHRANE RISK OF BIAS AND THE ROBINS-I FOR PRIMARY STUDIES

Question | Yes | No | Unclear
Clarity
1. Clear reporting with no discrepancies (Y/N)
2. Were eligibility criteria clear? (Y/N)
3. Were interventions adequately described? (Y/N)
4. Were the outcomes fully defined? (Y/N)
Bias Assessment
5. Random sequence generation: Selection bias (biased allocation to interventions) due to inadequate generation of a randomized sequence.
6. Allocation concealment: Selection bias (biased allocation to interventions) due to inadequate concealment of allocations prior to assignment.
7. Blinding of participants and personnel: Performance bias due to knowledge of the allocated interventions by participants during the study.
8. Blinding of outcome assessor (detection bias): Detection bias due to knowledge of the allocated interventions by outcome assessors.
9. Incomplete outcome data (attrition bias): Attrition bias due to amount, nature or handling of incomplete outcome data.
10. Selective Reporting (reporting bias): Reporting bias due to selective outcome reporting.
11. Intention-to-treat-analysis: Bias due to incomplete reporting and analysis according to group allocation.
12. If observational study, comparator group was sufficiently similar (and selected patients were all included or a random sample were included).
13. If observational study, Adjustment for confounders.; a. Crude analysis (unadjusted comparison between ADP and no ADP) [High RoB]; b. Regression adjustment or patient-matching (accounting for at least age, sex, and symptom duration OR a risk score) [Low RoB]; c. Regression adjustment or patient-matching (not accounting at least one of for age, sex, symptom duration, or risk score) [Moderate RoB]; d. Propensity score analysis (or equivalent) [Low RoB]

## APPENDIX C-2 AMSTAR2

Question | Rating
1. Did the research questions and inclusion criteria for the review include the components of PICO? | Yes | No
2. Did the report of the review contain an explicit statement that the review methods were established prior to the conduct of the review and did the report justify any significant deviations from the protocol? | Yes | Partial; Yes | No
3. Did the review authors explain their selection of the study designs for inclusion in the review? | Yes | No
4. Did the review authors use a comprehensive literature search strategy? | Yes | Partial; Yes | No
5. Did the review authors perform study selection in duplicate? | Yes | No
6. Did the review authors perform data extraction in duplicate? | Yes | No
7. Did the review authors provide a list of excluded studies and justify the exclusions? | Yes | Partial; Yes | No
8. Did the review authors describe the included studies in adequate detail? | Yes | Partial; Yes | No
9. Did the review authors use a satisfactory technique for assessing the risk of bias (RoB) in individual studies that were included in the review? | Yes | Partial; Yes | No
10. Did the review authors report on the sources of funding for the studies included in the review? | Yes | No
11. If meta-analysis was performed did the review authors use appropriate methods for statistical combination of results? | Yes | No | No meta-analysis conducted
12. If meta-analysis was performed, did the review authors assess the potential impact of RoB in individual studies on the results of the meta-analysis or other evidence synthesis? | Yes | No | No meta-analysis conducted
13. Did the review authors account for RoB in individual studies when interpreting/ discussing the results of the review? | Yes | No
14. Did the review authors provide a satisfactory explanation for, and discussion of, any heterogeneity observed in the results of the review? | Yes | No
15. If they performed quantitative synthesis did the review authors carry out an adequate investigation of publication bias (small study bias) and discuss its likely impact on the results of the review? | Yes | No | No meta-analysis conducted
16. Did the review authors report any potential sources of conflict of interest, including any funding they received for conducting the review? | Yes | No

Shea BJ, Reeves BC, Wells G, Thuku M, Hamel C, Moran J, Moher D, Tugwell P, Welch V, Kristjansson E, Henry DA. AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or non-randomised studies of healthcare interventions, or both. BMJ. 2017 Sep 21;358:j4008.28935701