# APPENDIX B EXCLUDED STUDIES

## APPENDIX B-1 EXCLUDED STUDIES

1 Alaniz-Camino F. The use of postoperative beta radiation in the treatment of pterygia. Ophthalmic Surg. Dec 1982;13(12):1022–5. At least 80% of participants treated before 1980.7162763
2 Bittard H, Schraub S, Bittard M. [Treatment of Peyronie’s disease by a combination of radiotherapy and surgery. Apropos of 51 cases]. Ann Urol (Paris). 1988;22(1):67–9. Traitement de la maladie de la peyronie par association radiochirurgicale. A propos de cinquante et un cas. At least 80% of participants treated before 1980.3369850
3 Boer J. Long-Term Follow-Up after Radiotherapy of Hidradenitis Suppurativa. Dermatology. 2022;238(2):244–250. doi:10.1159/000517252. At least 80% of participants treated before 1980.34134120
4 Campbell OR, Amendola BE, Brady LW. Recurrent pterygia: results of postoperative treatment with Sr-90 applicators. Radiology. Feb 1990;174(2):565–6. doi:10.1148/radiology.174.2.2296667. At least 80% of participants treated before 1980.2296667
5 Hayasaka S, Noda S, Yamamoto Y, Setogawa T. Postoperative instillation of low-dose mitomycin C in the treatment of primary pterygium. Am J Ophthalmol. Dec 15 1988;106(6):715–8. doi:10.1016/0002-9394(88)90706-4. At least 80% of participants treated before 1980.3143266
6 Miszczyk L, Jochymek B, Wozniak G. Retrospective evaluation of radiotherapy in plantar fasciitis. Br J Radiol. Oct 2007;80(958):829–34. doi:10.1259/bjr/79800547. At least 80% of participants treated before 1980.17875593
7 Viljoen IM, Goedhals L, Doman MJ. Peyronie’s disease--a perspective on the disease and the long-term results of radiotherapy. S Afr Med J. Jan 1993;83(1):19–20. At least 80% of participants treated before 1980.8424192
8 Wilder RB, Buatti JM, Kittelson JM, . Pterygium treated with excision and postoperative beta irradiation. Int J Radiat Oncol Biol Phys. 1992;23(3):533–7. doi:10.1016/0360-3016(92)90008-6. At least 80% of participants treated before 1980.1612953
9 Darzi MA, Chowdri NA, Kaul SK, Khan M. Evaluation of various methods of treating keloids and hypertrophic scars: a 10-year follow-up study. Br J Plast Surg. Jul 1992;45(5):374–9. doi:10.1016/0007-1226(92)90008-l. Date of publication <= 1980.1638291
10 Ernst H, Besserer A, Flemming I. [Irradiation prophylaxis of keloids and cicatricial hypertrophies (author’s transl)]. Strahlentherapie. Sep 1979;155(9):614–7. Strahlenprophylaxe von Keloiden und Narbenhypertrophien. Date of publication <= 1980.505467
11 Malaker A, Ellis F, Paine CH. Keloid scars: a new method of treatment combining surgery with interstitial radiotherapy. Clin Radiol. Apr 1976;27(2):179–83. doi:10.1016/s0009-9260(76)80141-9. Date of publication <= 1980.1277734
12 Narakula GK, Shenoy RK. A prospective clinical review of “multi model" approach for treating ear keloids. Indian J Plast Surg. Jan 2008;41(1):2–7. doi:10.4103/0970-0358.41103. No eligible outcome reported.19753193
13 Tsuge T, Aoki M, Akaishi S, Dohi T, Yamamoto H, Ogawa R. Geometric modeling and a retrospective cohort study on the usefulness of fascial tensile reductions in severe keloid surgery. Surgery. Feb 2020;167(2):504–509. doi:10.1016/j.surg.2019.07.028. No eligible outcome reported.31561991
14 Hermann RM, Trillmann A, Becker JN, Kaltenborn A, Nitsche M, Ruettermann M. Prospective evaluation of low-dose external beam radiotherapy (LD-EBRT) for painful trapeziometacarpal osteoarthritis (rhizarthrosis) on pain, function, and quality of life to calculate the required number of patients for a prospective randomized study. Med Sci (Basel). Oct 27 2021;9(4)doi:10.3390/medsci9040066. Not disease of interest.
15 Juniku N, Micke O, Seegenschmiedt MH, Muecke R. Radiotherapy for painful benign skeletal disorders: results of a retrospective clinical quality assessment. Strahlenther Onkol. Dec 2019;195(12):1068–1073. Radiotherapie bei schmerzhaften benignen muskuloskeletalen Erkrankungen : Ergebnisse einer retrospektiven klinischen Qualitätskontrolle. doi:10.1007/s00066-019-01514-w. Not disease of interest.31456003
16 Kishkovskiĭ AN, Dudarev AL. [Radiotherapy in the prevention of postoperative and traumatic complications]. Med Radiol (Mosk). May 1983;28(5):18–24. Luchevaia terapiia v preduprezhdenii posleoperatsionnykh i ranevykh oslozheniĭ. Not disease of interest.
17 Lo TC, Seckel BR, Salzman FA, Wright KA. Single-dose electron beam irradiation in treatment and prevention of keloids and hypertrophic scars. Radiother Oncol. Nov 1990;19(3):267–72. doi:10.1016/0167-8140(90)90153-n. Not disease of interest.2126387
18 Ott OJ, Jeremias C, Gaipl US, Frey B, Schmidt M, Fietkau R. Radiotherapy for calcaneodynia. Results of a single center prospective randomized dose optimization trial. Strahlenther Onkol. Apr 2013;189(4):329–34. doi:10.1007/s00066-012-0256-3. Not disease of interest.23443608
19 Reid R, Cooke H. Postoperative ionizing radiation in the management of heterotopic bone formation in the temporomandibular joint. J Oral Maxillofac Surg. Aug 1999;57(8):900–5; discussion 905-6. doi:10.1016/s0278-2391(99)90003-4. Not disease of interest.10437716
20 Zalewska J, Węgierska M, Barczyńska T, Waszczak M, Żuchowski P, Jeka S. Efficacy of radiation synovectomy (radiosynovectomy or radiosynoviorthesis) with yttrium-90 in exudative inflammation of synovial membrane of knee joints in patients with rheumatic diseases - preliminary report. Reumatologia. 2016;54(1):3–9. doi:10.5114/reum.2016.58754. Not disease of interest.27407269
21 Barragán VV, García AIA, García JF, Marín MJ, Vivas J, Rijo GJ. Perioperative interstitial high-dose-rate brachytherapy for keloids scar. J Contemp Brachytherapy. Feb 2022;14(1):29–34. doi:10.5114/jcb.2022.113547. Not intervention of interest.35233232
22 Basdew H, Mehilal R, Al-Mamgani A, . Adjunctive treatment of keloids: comparison of photodynamic therapy with brachytherapy. European journal of plastic surgery. 2013;36:289–294. Not intervention of interest.
23 Beyer DC. Pterygia: single-fraction postoperative beta irradiation. Radiology. Feb 1991;178(2):569–71. doi:10.1148/radiology.178.2.1987626. Not intervention of interest.1987626
24 Bijlard E, Timman R, Verduijn GM, Niessen FB, Hovius SER, Mureau MAM. Intralesional cryotherapy versus excision with corticosteroid injections or brachytherapy for keloid treatment: Randomised controlled trials. J Plast Reconstr Aesthet Surg. Jun 2018;71(6):847–856. doi:10.1016/j.bjps.2018.01.033. Not intervention of interest.29426811
25 Daurade M, Breton P, Rouard N, Lorchel F, Ibrahim B, Sigaux N. Efficacy of surgical excision and brachytherapy in the treatment of keloids: a retrospective cohort study. Adv Skin Wound Care. Nov 2020;33(11):1–6. doi:10.1097/01.ASW.0000717228.02752.4e. Not intervention of interest.
26 Ehlich H, Kresnik E, Klett R, Freudenberg LS, Kampen WU. Intra-articular treatment of digital osteoarthritis by radiosynoviorthesis-clinical outcome in long-term follow-up. Clin Nucl Med. Nov 1 2022;47(11):943–947. doi:10.1097/rlu.0000000000004322. Not intervention of interest.35776838
27 Fuenmayor P, Quiñonez H, Salas R, Pujadas Z. Outcomes of surgical excision and high-dose-rate brachytherapy for earlobe keloids. World J Plast Surg. Jan 2021;10(1):78–84. doi:10.29252/wjps.10.1.78. Not intervention of interest.
28 Jiang P, Baumann R, Dunst J, . Perioperative interstitial high-dose-rate brachytherapy for the treatment of recurrent keloids: feasibility and early results. Int J Radiat Oncol Biol Phys. Mar 1 2016;94(3):532–6. doi:10.1016/j.ijrobp.2015.11.008. Not intervention of interest.26867882
29 Jürgenliemk-Schulz IM, Hartman LJ, Roesink JM, . Prevention of pterygium recurrence by postoperative single-dose beta-irradiation: a prospective randomized clinical double-blind trial. Int J Radiat Oncol Biol Phys. Jul 15 2004;59(4):1138–47. doi:10.1016/j.ijrobp.2003.12.021. Not intervention of interest.15234049
30 Liepe K, Baehr M. Radiosynovectomy is effective in thumb basal joint arthritis. Ann Nucl Med. Nov 2021;35(11):1232–1239. doi:10.1007/s12149-021-01665-w. Not intervention of interest.34350545
31 Maalej M, Frikha H, Bouaouina N, . [[Intraoperative brachytherapy in the management of keloids. Apropos of 114 cases]]. Cancer Radiother. Jul–Aug 2000;4(4):274–8. Place de la curiethérapie dans le traitement des chéloïdes. A propos de 114 cas. doi:10.1016/s1278-3218(00)80005-0. Not intervention of interest.10994391
32 Manjunath KN, Venkatesh MS, Alva R, . Efficacy of surgical excision and adjuvant high-dose rate brachytherapy in treatment of keloid: our experience. J Cutan Aesthet Surg. Jul–Sep 2021;14(3):337–343. doi:10.4103/jcas.Jcas_120_16. Not intervention of interest.34908777
33 Mourits MP, Wyrdeman HK, Jurgenliemk-Schulz IM, Bidlot E. Favorable long-term results of primary pterygium removal by bare sclera extirpation followed by a single 90Strontium application. Eur J Ophthalmol. May–Jun 2008;18(3):327–31. doi:10.1177/112067210801800301. Not intervention of interest.18465710
34 Ozen S, Doganci EB, Ozyuvali A, Yalcin AP. Effectiveness of continuous versus pulsed short-wave diathermy in the management of knee osteoarthritis: A randomized pilot study. Caspian J Intern Med. Fall 2019;10(4):431–438. doi:10.22088/cjim.10.4.431. Not intervention of interest.31814942
35 Piccolo D, Crisman G, Bovani B, . Combined laser treatment for ear keloids: case series: comparison between two mini-invasive protocols: comparison between two mini-invasive protocols. J Cosmet Dermatol. Jan 2022;21(1):296–306. doi:10.1111/jocd.14590. Not intervention of interest.34757676
36 Reeboonlap N, Satitsmithpong N, Phisitkul P, Charakorn K. Outcome of plantar fasciitis treatment using monochrome infrared irradiation. J Med Assoc Thai. Oct 2012;95 Suppl 10:S147–50. Not intervention of interest.
37 Rio E, Bardet E, Peuvrel P, Pannier M, Dreno B. Perioperative interstitial brachytherapy for recurrent keloid scars. Plast Reconstr Surg. Jul 2009;124(1):180e–181e. doi:10.1097/PRS.0b013e3181a83b7e. Not intervention of interest.
38 Robert Y, Pauli L, Gysin P, Gloor B, Hendrickson P. Protracted ruthenium treatment of recurrent pterygium. Graefes Arch Clin Exp Ophthalmol. 1992;230(3):233–6. doi:10.1007/bf00176295. Not intervention of interest.1597288
39 Shamim SA, Arora G, Jha P, . Comparison of Lutetium-177 tin colloid and Rhenium-188 tin colloid radiosynovectomy in chronic knee arthritis. Nucl Med Commun. Aug 2020;41(8):721–726. doi:10.1097/mnm.0000000000001210. Not intervention of interest.32404646
40 Szerb I, Gál T, Kiss D, Nagy V, Hangody L. Efficacy assessment of radiosynoviorthesis on the progression of radiological osteoarthritic features of hip and ankle joint in patients with osteoarthritis and rheumatoid arthritis. Nuklearmedizin. Jun 2020;59(3):269–275.32074661
41 Bewertung der Wirksamkeit der Radiosynoviorthese auf das Fortschreiten der radiologischen Arthrosezeichen von Hüfte und Sprunggelenk bei Patienten mit Arthrose und rheumatoider Arthritis. doi:10.1055/a-1108-1187. Not intervention of interest.
42 van Leeuwen MCE, Stokmans SC, Bulstra AJ, Meijer OWM, van Leeuwen PAM, Niessen FB. High-dose-rate brachytherapy for the treatment of recalcitrant keloids: a unique, effective treatment protocol. Plast Reconstr Surg. Sep 2014;134(3):527–534. doi:10.1097/prs.0000000000000415. Not intervention of interest.25158710
43 Yossi S, Krhili S, Mesgouez-Nebout N, . Adjuvant treatment of keloid scars: electrons or brachytherapy? Cancer Radiotherapie: Journal de la Societe Francaise de Radiotherapie Oncologique. 2013;17(1):21–25. Not intervention of interest.23332126
44 Donaubauer AJ, Zhou JG, Ott OJ, . Low dose radiation therapy, particularly with 0.5 Gy, improves pain in degenerative joint disease of the fingers: results of a retrospective analysis. Int J Mol Sci. Aug 14 2020;21(16)doi:10.3390/ijms21165854. Not population of interest.
45 Hess CB, Stein-Wexler R, Qi L, Davids JR, Fragoso RC. Outcomes of preoperative versus postoperative radiation for heterotopic ossification prevention in children with neuromuscular hip dysplasia undergoing proximal femoral resection. J Pediatr Orthop. Feb 2019;39(2):e102–e107. doi:10.1097/bpo.0000000000001018. Not population of interest.29068805
46 Rösler H, Zapf S, Kuffner H, Wissen-Siegert I, Kutzner J. Radiotherapy in scar-induced keloid. Fortschritte der Medizin. 1993;111(4):46–49. Not population of interest.
47 de Farias CC, Sterlenich T, de Sousa LB, Vieira LA, Gomes J. Randomized trial comparing multilayer amniotic membrane transplantation with scleral and corneal grafts for the treatment of scleral thinning after pterygium surgery associated with beta therapy. Cornea. Nov 2014;33(11):1197–204. doi:10.1097/ico.0000000000000207. Not reporting quality of interest.25222001
48 Furtado F, Hochman B, Farber PL, Muller MC, Hayashi LF, Ferreira LM. Psychological stress as a risk factor for postoperative keloid recurrence. J Psychosom Res. Apr 2012;72(4):282–7. doi:10.1016/j.jpsychores.2011.12.010. Not reporting quality of interest.22405222
49 Handel M, Brettschneider J, Köck FX, Anders S, Perlick L, Sell S. [Risk factors associated with heterotopic ossifications in primary total hip arthroplasty]. Z Orthop Ihre Grenzgeb. Sep–Oct 2004;142(5):564–70. Risikofaktoren für heterotope Ossifikationen in der primären Hüftgelenkstotalendoprothetik. doi:10.1055/s-2004-832310. Not reporting quality of interest.15472766
50 Kutzner J, Schneider L, Seegenschmiedt MH. [Radiotherapy of keloids. Patterns of care study - results]. Strahlenther Onkol. Jan 2003;179(1):54–8. Strahlentherapie des Keloids in Deutschland Patterns-of-Care-Studie -- Ergebnisse einer Umfrage. doi:10.1007/s00066-003-1023-2. Not reporting quality of interest.12540986
51 Mavrogenis AF, Guerra G, Staals EL, Bianchi G, Ruggieri P. A classification method for neurogenic heterotopic ossification of the hip. J Orthop Traumatol. Jun 2012;13(2):69–78. doi:10.1007/s10195-012-0193-z. Not reporting quality of interest.22476356
52 Qi Z, Liang W, Wang Y, . “X”-shaped incision and keloid skin-flap resurfacing: a new surgical method for auricle keloid excision and reconstruction. Dermatol Surg. Aug 2012;38(8):1378–82. doi:10.1111/j.1524-4725.2012.02455.x. Not reporting quality of interest.22671999
53 Sheybani A, TenNapel MJ, Lack WD, . Risk of radiation-induced malignancy with heterotopic ossification prophylaxis: a case-control analysis. Int J Radiat Oncol Biol Phys. Jul 1 2014;89(3):584–9. doi:10.1016/j.ijrobp.2014.03.008. Not reporting quality of interest.24803038
54 (S002) A 15-Year review of radiation therapy for keloids at two institutions. Oncology (Williston Park). Apr 2016;30 Suppl. Other.
55 Cadosch D, Bauer S, Gautschi OP, Filgueira L, Zellweger R. [Surgical arthrolysis in patients with high-grade heterotopic ossification after hip joint endoprosthesis]. Unfallchirurg. Jul 2008;111(7):535–8. Operative Arthrolyse bei schwergradiger heterotoper Ossifikation nach Hüftgelenksendoprothese. doi:10.1007/s00113-008-1462-4. Other.18566788
56 Chen HC, Ou SY, Lai YL. Combined surgery and irradiation for treatment of hypertrophic scars and keloids. Zhonghua Yi Xue Za Zhi (Taipei). Apr 1991;47(4):249–54. Other.1646674
57 Monselise M, Schwartz M, Politi F, Barishak YR. Pterygium and beta irradiation. Acta Ophthalmol (Copenh). Apr 1984;62(2):315–9. doi:10.1111/j.1755-3768.1984.tb08408.x. Other.6426246
58 Bijlard E, Timman R, Verduijn GM, . Intralesional cryotherapy versus excision and corticosteroids or brachytherapy for keloid treatment: study protocol for a randomised controlled trial. Trials. Dec 19 2013;14:439. doi:10.1186/1745-6215-14-439. Protocol.24354714
59 Holtmann H, Niewald M, Prokein B, Graeber S, Ruebe C. Randomized multicenter follow-up trial on the effect of radiotherapy for plantar fasciitis (painful heels spur) depending on dose and fractionation - a study protocol. Radiat Oncol. Jan 20 2015;10:23. doi:10.1186/s13014-015-0327-6. Protocol.25601335
60 Kim BH, Shin K, Kim MJ, . Low-dose radiation therapy for patients with knee osteoarthritis (LORD-KNEA): a protocol for a sham-controlled randomised trial. BMJ Open. Feb 10 2023;13(2):e069691. doi:10.1136/bmjopen-2022-069691. Protocol.
61 Niewald M, Seegenschmiedt MH, Micke O, Gräber S. Randomized multicenter trial on the effect of radiotherapy for plantar Fasciitis (painful heel spur) using very low doses--a study protocol. Radiat Oncol. Sep 18 2008;3:27. doi:10.1186/1748-717x-3-27. Protocol.18801159
62 Hautmann MG, Neumaier U, Kölbl O. Re-irradiation for painful heel spur syndrome. Retrospective analysis of 101 heels. Strahlenther Onkol. Mar 2014;190(3):298–303. doi:10.1007/s00066-013-0462-7. Re-irradiation.24452814
63 Hautmann MG, Rechner P, Hipp M, . Re-irradiation for osteoarthritis-retrospective analysis of 217 joints. Strahlenther Onkol. Dec 2019;195(12):1060–1067. Rebestrahlung bei Arthrose – retrospektive Analyse von 217 Gelenken. doi:10.1007/s00066-019-01500-2. Re-irradiation.31346673
64 Emad M, Omidvari S, Dastgheib L, Mortazavi A, Ghaem H. Surgical excision and immediate postoperative radiotherapy versus cryotherapy and intralesional steroids in the management of keloids: a prospective clinical trial. Med Princ Pract. 2010;19(5):402–5. doi:10.1159/000316381. Sample size <=10.20639666
65 Jackson I, Bhageshpur R, DiNick V, Khan A, Bhaloo S. Investigation of recurrence rates among earlobe keloids utilizing various postoperative therapeutic modalities. European Journal of Plastic Surgery. 2001;24(2):88–95. Sample size <=10.
66 Moriarty AP, Crawford GJ, McAllister IL, Constable IJ. Severe corneoscleral infection. A complication of beta irradiation scleral necrosis following pterygium excision. Arch Ophthalmol. Jul 1993;111(7):947–51. doi:10.1001/archopht.1993.01090070065021. Sample size <=10.8328937
67 Rubenstein JH, Salenius SA, Blitzer PH, Katin MJ, Dosoretz DE. Prevention of heterotopic bone formation with low dose radiation therapy. J Fla Med Assoc. Dec 1992;79(12):828–32. Sample size <=10.1474368
68 Salazar D, Golz A, Israel H, Marra G. Heterotopic ossification of the elbow treated with surgical resection: risk factors, bony ankylosis, and complications. Clin Orthop Relat Res. Jul 2014;472(7):2269–75. doi:10.1007/s11999-014-3591-0. Sample size <=10.24711127
69 Widmann RF, Do TT, Doyle SM, Burke SW, Root L. Resection arthroplasty of the hip for patients with cerebral palsy: an outcome study. J Pediatr Orthop. Nov–Dec 1999;19(6):805–10. Sample size <=10.10573353
70 Ball C, Izadi D, Verjee LS, Chan J, Nanchahal J. Systematic review of non-surgical treatments for early dupuytren’s disease. BMC Musculoskelet Disord. Aug 15 2016;17(1):345. doi:10.1186/s12891-016-1200-y. Systematic review.27526686
71 Blokhuis TJ, Frölke JP. Is radiation superior to indomethacin to prevent heterotopic ossification in acetabular fractures?: a systematic review. Clin Orthop Relat Res. Feb 2009;467(2):526–30. doi:10.1007/s11999-008-0532-9. Systematic review.18820982
72 Bueno TSP, Godoy GP, Furukava RB, . Heterotopic ossification in acetabular fractures: systematic review and meta-analysis of prophylaxis. Acta Ortop Bras. Nov–Dec 2021;29(6):331–340. doi:10.1590/1413-785220212906244689. Systematic review.34849100
73 Cheraghi N, Cognetta A, Jr., Goldberg D. Radiation therapy for the adjunctive treatment of surgically excised keloids: A review. J Clin Aesthet Dermatol. Aug 2017;10(8):12–15. Systematic review.
74 Ellis MM, Jones LR, Siddiqui F, Sunkara PR, Ozog DM. The efficacy of surgical excision plus adjuvant multimodal therapies in the treatment of keloids: a systematic review and meta-analysis. Dermatol Surg. Aug 2020;46(8):1054–1059. doi:10.1097/dss.0000000000002362. Systematic review.32224709
75 Gold MH, Nestor MS, Berman B, Goldberg D. Assessing keloid recurrence following surgical excision and radiation. Burns Trauma. 2020;8:tkaa031. doi:10.1093/burnst/tkaa031. Systematic review.33225004
76 Henstenburg JM, Sherman M, Ilyas AM. Comparing options for heterotopic ossification prophylaxis following elbow trauma: a systematic review and meta-analysis. J Hand Microsurg. Jul 2021;13(3):189–195. doi:10.1055/s-0040-1721880. Systematic review.34511838
77 Hsieh CL, Chi KY, Lin WY, Lee LT. Timing of adjuvant radiotherapy after keloid excision: a systematic review and meta-analysis. Dermatol Surg. Nov 1 2021;47(11):1438–1443. doi:10.1097/dss.0000000000003165. Systematic review.34417379
78 Hu ZH, Chen W, Sun JN, . Radiotherapy for the prophylaxis of heterotopic ossification after total hip arthroplasty: a systematic review and meta-analysis of randomized controlled trails. Med Dosim. Spring 2021;46(1):65–73. doi:10.1016/j.meddos.2020.07.010. Systematic review.32928622
79 Hwang NH, Chang JH, Lee NK, Yang KS. Effect of the biologically effective dose of electron beam radiation therapy on recurrence rate after keloid excision: A meta-analysis. Radiother Oncol. Aug 2022;173:146–153. doi:10.1016/j.radonc.2022.06.003. Systematic review.35688397
80 Kadhum M, Smock E, Khan A, Fleming A. Radiotherapy in Dupuytren’s disease: a systematic review of the evidence. J Hand Surg Eur Vol. Sep 2017;42(7):689–692. doi:10.1177/1753193417695996. Systematic review.28490266
81 Kal HB, Veen RE. Biologically effective doses of postoperative radiotherapy in the prevention of keloids. Dose-effect relationship. Strahlenther Onkol. Nov 2005;181(11):717–23. doi:10.1007/s00066-005-1407-6. Systematic review.16254707
82 Kal HB, Veen RE, Jürgenliemk-Schulz IM. Dose-effect relationships for recurrence of keloid and pterygium after surgery and radiotherapy. Int J Radiat Oncol Biol Phys. May 1 2009;74(1):245–51. doi:10.1016/j.ijrobp.2008.12.066. Systematic review.19362243
83 Mankowski P, Kanevsky J, Tomlinson J, Dyachenko A, Luc M. Optimizing radiotherapy for keloids: a meta-analysis systematic review comparing recurrence rates between different radiation modalities. Ann Plast Surg. Apr 2017;78(4):403–411. doi:10.1097/sap.0000000000000989. Systematic review.28177974
84 Mathew KK, Marchand KB, Tarazi JM, . Heterotopic ossification prophylaxis following operative fixation of acetabular fractures: a systematic review. Surgical Technology International. 2022;40. Systematic review.
85 Milakovic M, Popovic M, Raman S, Tsao M, Lam H, Chow E. Radiotherapy for the prophylaxis of heterotopic ossification: a systematic review and meta-analysis of randomized controlled trials. Radiother Oncol. Jul 2015;116(1):4–9. doi:10.1016/j.radonc.2015.05.022. Systematic review.26163090
86 Miles OJ, Zhou J, Paleri S, Fua T, Ramakrishnan A. Chest keloids: effect of surgical excision and adjuvant radiotherapy on recurrence, a systematic review and meta-analysis. ANZ J Surg. Jun 2021;91(6):1104–1109. doi:10.1111/ans.16561. Systematic review.33438368
87 Minten MJ, Mahler E, den Broeder AA, Leer JW, van den Ende CH. The efficacy and safety of low-dose radiotherapy on pain and functioning in patients with osteoarthritis: a systematic review. Rheumatol Int. Jan 2016;36(1):133–42. doi:10.1007/s00296-015-3337-7. Systematic review.26747050
88 Pakos EE, Ioannidis JP. Radiotherapy vs. nonsteroidal anti-inflammatory drugs for the prevention of heterotopic ossification after major hip procedures: a meta-analysis of randomized trials. Int J Radiat Oncol Biol Phys. Nov 1 2004;60(3):888–95. doi:10.1016/j.ijrobp.2003.11.015. Systematic review.15465207
89 Ploumis A, Belbasis L, Ntzani E, Tsekeris P, Xenakis T. Radiotherapy for prevention of heterotopic ossification of the elbow: a systematic review of the literature. J Shoulder Elbow Surg. Nov 2013;22(11):1580–8. doi:10.1016/j.jse.2013.07.045. Systematic review.24138821
90 Popovic M, Agarwal A, Zhang L, . Radiotherapy for the prophylaxis of heterotopic ossification: a systematic review and meta-analysis of published data. Radiother Oncol. Oct 2014;113(1):10–7. doi:10.1016/j.radonc.2014.08.025. Systematic review.25220370
91 Shapira J, Yelton MJ, Chen JW, . Efficacy of NSAIDs versus radiotherapy for heterotopic ossification prophylaxis following total hip arthroplasty in high-risk patients: a systematic review and meta-analysis. Hip Int. Sep 2022;32(5):576–590. doi:10.1177/1120700021991115. Systematic review.33736491
92 Shin JY, Lee JW, Roh SG, Lee NH, Yang KM. A comparison of the effectiveness of triamcinolone and radiation therapy for ear keloids after surgical excision: a systematic review and meta-analysis. Plast Reconstr Surg. Jun 2016;137(6):1718–1725. doi:10.1097/prs.0000000000002165. Systematic review.27219228
93 Sigaux N, Jacquemart M, Cousin AS, Lorchel F, Breton P. Association of surgical excision and brachytherapy for the management of keloids. J Stomatol Oral Maxillofac Surg. Jun 2017;118(3):161–166. doi:10.1016/j.jormas.2017.04.002. Systematic review.28400319
94 Siotos C, Uzosike AC, Hong H, . Keloid excision and adjuvant treatments: a network meta-analysis. Ann Plast Surg. Aug 2019;83(2):154–162. doi:10.1097/sap.0000000000001951. Systematic review.31232819
95 Tchero H, Herlin C, Bekara F, Fluieraru S, Teot L. Hidradenitis suppurativa: a systematic review and meta-analysis of therapeutic interventions. Indian J Dermatol Venereol Leprol. May–Jun 2019;85(3):248–257. doi:10.4103/ijdvl.IJDVL_69_18. Systematic review.30924446
96 Thompson AM, Seivright J, Atluri S, . Radiotherapy for hidradenitis suppurativa: a systematic review. Dermatology. 2021;237(3):357–364. doi:10.1159/000514027. Systematic review.33535201
97 van Leeuwen MC, Stokmans SC, Bulstra AE, . Surgical excision with adjuvant irradiation for treatment of keloid scars: a systematic review. Plast Reconstr Surg Glob Open. Jul 2015;3(7):e440. doi:10.1097/gox.0000000000000357. Systematic review.26301129
98 Vavken P, Castellani L, Sculco TP. Prophylaxis of heterotopic ossification of the hip: systematic review and meta-analysis. Clin Orthop Relat Res. Dec 2009;467(12):3283–9. doi:10.1007/s11999-009-0924-5. Systematic review.19517202
99 Walter WL. Another look at pterygium surgery with postoperative beta radiation. Ophthalmic Plast Reconstr Surg. Dec 1994;10(4):247–52. doi:10.1097/00002341-199412000-00004. Systematic review.7865444
100 Xu J, Yang E, Yu NZ, Long X. Radiation therapy in keloids treatment: history, strategy, effectiveness, and complication. Chin Med J (Engl). Jul 20 2017;130(14):1715–1721. doi:10.4103/0366-6999.209896. Systematic review.28685723
101 Zeng W, Liu Z, Dai H, . Anti-fibrotic, anti-VEGF or radiotherapy treatments as adjuvants for pterygium excision: a systematic review and network meta-analysis. BMC Ophthalmol. Nov 25 2017;17(1):211. doi:10.1186/s12886-017-0601-5. Systematic review.29178848

## APPENDIX B-2 NOT EXTRACTED PER BEST EVIDENCE APPROACH

### Dupuytren Contracture/Disease: 5 Exclusions

1 Keilholz L, Seegenschmiedt MH, Born AD, Sauer R. [Radiotherapy in the early stage of Dupuytren’s disease. The indications, technic and long-term results]. Strahlenther Onkol. Jan 1997;173(1):27–35. Radiotherapie im frühen Stadium des Morbus Dupuytren. Indikation, Technik und Langzeitergebnisse. doi:10.1007/bf03039191 9082583
2 Schuster J, Saraiya S, Tennyson N, Nedelka M, Mukhopadhyay N, Weiss E. Patient-reported outcomes after electron radiation treatment for early-stage palmar and plantar fibromatosis. Pract Radiat Oncol. Nov–Dec 2015;5(6):e651–8. doi:10.1016/j.prro.2015.06.010 26421835
3 Seegenschmiedt MH, Olschewski T, Guntrum F. [Optimization of radiotherapy in Dupuytren’s disease. Initial results of a controlled trial]. Strahlenther Onkol. Feb 2001;177(2):74–81. Optimierung der Radiotherapie bei Morbus Dupuytren. Erste Ergebnisse einer kontrollierten Studie. doi:10.1007/pl00002386 11233838
4 Seegenschmiedt MH, Olschewski T, Guntrum F. Radiotherapy optimization in early-stage Dupuytren’s contracture: first results of a randomized clinical study. Int J Radiat Oncol Biol Phys. Mar 1 2001;49(3):785–98. doi:10.1016/s0360-3016(00)00745-8 11172962
5 Weinzierl G, Flügel M, Geldmacher J. [Lack of effectiveness of alternative non-surgical treatment procedures of Dupuytren contracture]. Chirurg. Jun 1993;64(6):492–4. Fehlen der Effektivität der alternativ nichtchirurgischen Behandlungsverfahren bei Morbus Dupuytren.8359061

### Hetertopic Ossification: 129 Exclusions (2 Duplicates)

1 Alberti W, Quack G, Krischke W, Lommatzsch A, Huyer C, Krahl H. [Prevention of heterotopic ossification by radiotherapy following total hip prosthesis]. Dtsch Med Wochenschr. Jul 14 1995;120(28–29):983–9. Verhinderung ektoper Ossifikationen nach Totalendoprothese des Hüftgelenks durch Strahlentherapie. doi:10.1055/s-2008-1055435 7621742
2 Alberti W, Quack G, Krischke W, Lommatzsch A, Huyer C, Krahl H. [Prevention of heterotopic ossification by radiotherapy following total hip prosthesis]. Dtsch Med Wochenschr. Jul 14 1995;120(28–29):983–9. Verhinderung ektoper Ossifikationen nach Totalendoprothese des Hüftgelenks durch Strahlentherapie. doi:10.1055/s-2008-1055435 7621742
3 Anglen JO, Moore KD. Prevention of heterotopic bone formation after acetabular fracture fixation by single-dose radiation therapy: a preliminary report. J Orthop Trauma. 1996;10(4):258–63. doi:10.1097/00005131-199605000-00006 8723404
4 Anthony P, Keys H, Evarts CM, Rubin P, Lush C. Prevention of heterotopic bone formation with early post operative irradiation in high risk patients undergoing total hip arthroplasty: comparison of 10.00 Gy vs 20.00 Gy schedules. Int J Radiat Oncol Biol Phys. Mar 1987;13(3):365–9. doi:10.1016/0360-3016(87)90010-1 3104246
5 Archdeacon MT, d’Heurle A, Nemeth N, Budde B. Is preoperative radiation therapy as effective as postoperative radiation therapy for heterotopic ossification prevention in acetabular fractures? Clin Orthop Relat Res. Nov 2014;472(11):3389–94. doi:10.1007/s11999-014-3670-2 24894347
6 Ashton LA, Bruce W, Goldberg J, Walsh W. Prevention of heterotopic bone formation in high risk patients post-total hip arthroplasty. J Orthop Surg (Hong Kong). Dec 2000;8(2):53–57. doi:10.1177/230949900000800210
7 Balboni TA, Gaccione P, Gobezie R, Mamon HJ. Shielding of the hip prosthesis during radiation therapy for heterotopic ossification is associated with increased failure of prophylaxis. Int J Radiat Oncol Biol Phys. Apr 1 2007;67(5):1499–505. doi:10.1016/j.ijrobp.2006.11.007 17234358
8 Blount LH, Thomas BJ, Tran L, Selch MT, Sylvester JE, Parker RG. Postoperative irradiation for the prevention of heterotopic bone: analysis of different dose schedules and shielding considerations. Int J Radiat Oncol Biol Phys. Sep 1990;19(3):577–81. doi:10.1016/0360-3016(90)90483-z 2211206
9 Boffeli TJ, Pfannenstein RR, Thompson JC. Radiation therapy for recurrent heterotopic ossification prophylaxis after partial metatarsal amputation. J Foot Ankle Surg. May–Jun 2015;54(3):345–9. doi:10.1053/j.jfas.2014.07.010 25746770
10 Boissonneault A, Harkin E, Slobogean G, . Is external beam radiation therapy really associated with low rates of heterotopic ossification after acetabular surgery? J Orthop Trauma. Aug 1 2023;37(8):382–385. doi:10.1097/bot.0000000000002598 36941239
11 Braun W. [Irradiation for the prevention of heterotopic ossification following surgery of the hip and knee joint. Report of initial experiences]. Chirurg. Nov 1989;60(11):795–800. Die Bestrahlung zur Prophylaxe heterotoper Ossifikationen nach Eingriffen am Hüft- und Ellbogengelenk. Bericht über erste Erfahrungen.2510977
12 Braun K. [Preoperative radiation for prevention of heterotopic ossifications after hip endoprosthesis replacement]. Z Orthop Ihre Grenzgeb. Mar–Apr 1999;137(2):Oa22–3. Präoperative Radiatio zur Prophylaxe heterotoper Ossifikationen nach endoprothetischem Hüftgelenkersatz.10408048
13 Brückl R, Frey M. [Prevention of para-articular ossifications by radiotherapy after cementless total hip endoprosthesis implantation]. Z Orthop Ihre Grenzgeb. Sep–Oct 1997;135(5):430–3. Prophylaxe paraartikulärer Ossifikationen durch Strahlentherapie nach zementloser Hüft-TEP-Implantation. doi:10.1055/s-2008-1039412 9446436
14 Burd TA, Lowry KJ, Anglen JO. Indomethacin compared with localized irradiation for the prevention of heterotopic ossification following surgical treatment of acetabular fractures. J Bone Joint Surg Am. Dec 2001;83(12):1783–8. doi:10.2106/00004623-200112000-00003 11741055
15 Burnet NG, Nasr P, Yip G, . Prophylactic radiotherapy against heterotopic ossification following internal fixation of acetabular fractures: a comparative estimate of risk. Br J Radiol. Oct 2014;87(1042):20140398. doi:10.1259/bjr.20140398 25089852
16 Cadieux CL, DesRosiers C, McMullen K. Risks of secondary malignancies with heterotopic bone radiation therapy for patients younger than 40 years. Med Dosim. Autumn 2016;41(3):212–5. doi:10.1016/j.meddos.2016.02.001 27156238
17 Chao ST, Lee SY, Borden LS, Joyce MJ, Krebs VE, Suh JH. External beam radiation helps prevent heterotopic bone formation in patients with a history of heterotopic ossification. J Arthroplasty. Aug 2006;21(5):731–6. doi:10.1016/j.arth.2005.08.014 16877161
18 Childs III HA, Cole T, Falkenberg E, . A prospective evaluation of the timing of postoperative radiotherapy for preventing heterotopic ossification following traumatic acetabular fractures. International Journal of Radiation Oncology* Biology* Physics. 2000;47(5):1347–1352.10889389
19 Cichos KH, Spitler CA, Quade JH, Almaguer A, McGwin G, Jr., Ghanem ES. Do Indomethacin or Radiation for Heterotopic Ossification Prophylaxis Increase the Rates of Infection or Wound Complications After Acetabular Fracture Surgery? J Orthop Trauma. Sep 2020;34(9):455–461. doi:10.1097/bot.0000000000001775 32815831
20 Cipriano C, Pill SG, Rosenstock J, Keenan MA. Radiation therapy for preventing recurrence of neurogenic heterotopic ossification. Orthopedics. Sep 2009;32(9)doi:10.3928/01477447-20090728-33
21 Citak M, Backhaus M, Kälicke T, . [Treatment of heterotopic ossification after spinal cord injury - clinical outcome after single-dose radiation therapy]. Z Orthop Unfall. Jan 2011;149(1):90–3. Therapie der heterotopen Ossifikation bei frischem Rückenmarkstrauma - Klinisches Outcome nach einmaliger Radiatio. doi:10.1055/s-0030-1250688 21328187
22 Citak M, Grasmücke D, Cruciger O, . Heterotopic ossification of the shoulder joint following spinal cord injury: an analysis of 21 cases after single-dose radiation therapy. Spinal Cord. Apr 2016;54(4):303–5. doi:10.1038/sc.2015.182 26503223
23 Citak M, Grasmücke D, Suero EM, . The roles of serum alkaline and bone alkaline phosphatase levels in predicting heterotopic ossification following spinal cord injury. Spinal Cord. May 2016;54(5):368–70. doi:10.1038/sc.2015.211 26643987
24 Cornes PG, Shahidi M, Glees JP. Heterotopic bone formation: irradiation of high risk patients. Br J Radiol. May 2002;75(893):448–52. doi:10.1259/bjr.75.893.750448 12036839
25 dʼHeurle A, Archdeacon MT, Hiratzka S, Casstevens C, Finnan R, McCoy B. Do surrogates of injury severity influence the occurrence of heterotopic ossification in fractures of the acetabulum? J Orthop Trauma. Apr 2016;30(4):213–6. doi:10.1097/bot.0000000000000490 26606599
26 D’Lima DD, Venn-Watson EJ, Tripuraneni P, Colwell CW. Indomethacin versus radiation therapy for heterotopic ossification after hip arthroplasty. Orthopedics. Dec 2001;24(12):1139–43. doi:10.3928/0147-7447-20011201-11 11770090
27 Daugherty LC, Bell JR, Fisher BJ, . Radiation prophylaxis as primary prevention of heterotopic ossification of the knee: classification of disease and indications for treatment. Journal of Radiation Oncology. 2013;2:87–94.
28 Davis JA, Roper B, Munz JW, . Does postoperative radiation decrease heterotopic ossification after the Kocher-Langenbeck Approach for acetabular fracture? Clin Orthop Relat Res. Jun 2016;474(6):1430–5. doi:10.1007/s11999-015-4609-y 26497882
29 DeFlitch CJ, Stryker JA. Postoperative hip irradiation in prevention of heterotopic ossification: causes of treatment failure. Radiology. Jul 1993;188(1):265–70. doi:10.1148/radiology.188.1.8511309 8511309
30 Ebinger T, Roesch M, Kiefer H, Kinzl L, Schulte M. Influence of etiology in heterotopic bone formation of the hip. J Trauma. Jun 2000;48(6):1058–62. doi:10.1097/00005373-200006000-00010 10866251
31 Effenberger H, Ramsauer T, Kranzinger M, Grethen C, Dorn U. [Prophylaxis of heterotopic ossification in hip revisions with 7 Gy single-dose radiation]. Z Orthop Ihre Grenzgeb. May–Jun 2002;140(3):317–22. Ossifikationsprophylaxe bei Hüft-Wechseloperationen mit 7-Gy-Einzelbestrahlung. doi:10.1055/s-2002-32472 12085298
32 Eulert J, Knelles D, Barthel T. [Heterotopic ossifications]. Unfallchirurg. Aug 1997;100(8):667–74. Heterotope Ossifikationen. doi:10.1007/s001130050173 9381216
33 Fingeroth RJ, Ahmed AQ. Single dose 6 Gy prophylaxis for heterotopic ossification after total hip arthroplasty. Clin Orthop Relat Res. Aug 1995;(317):131–40.
34 Freije SL, Kushdilian MV, Burney HN, Zang Y, Saito NG. A retrospective analysis of 287 patients undergoing prophylactic radiation therapy for the prevention of heterotopic ossification. Adv Radiat Oncol. May–Jun 2021;6(3):100625. doi:10.1016/j.adro.2020.11.010 34195485
35 Gehl HB, Karstens JH, Casser HR, Savvidis E, Ammon J. [The prevention of ectopic ossification in total hip endoprostheses. Studies on field volume, total dosage and timing of postoperative radiotherapy]. Rontgenpraxis. Apr 1991;44(4):117–21. Prophylaxe ektoper Ossifikationen bei Hüftgelenktotalendoprothesen. Untersuchungen über Zielvolumen, Gesamtdosis und Zeitpunkt der postoperativen Radiotherapie.1905061
36 Geller JS, Allegra PR, Seldon CS, . Prophylactic radiotherapy for prevention of heterotopic ossification after periacetabular fractures: A review of efficacy and associated conditions. J Surg Orthop Adv. Summer 2022;31(2):113–118.35820098
37 Georhakopoulos I, Kouloulias V, Kougiountzopoulou A, . Radiation therapy for the prevention of heterotopic ossification: Efficacy and toxicity of single fraction radiotherapy. Orthop Rev (Pavia). Aug 6 2020;12(2):8577. doi:10.4081/or.2020.8577 32922703
38 Goldmann AR, Seegenschmiedt M, Andreas P, Hohmann D, Sauer R, Beck H. [Radiation therapy in the prevention of periarticular, heterotopic ossification following implantation of a total hip endoprosthesis]. Z Orthop Ihre Grenzgeb. Mar–Apr 1993;131(2):151–5. Strahlentherapie zur Prophylaxe von periartikulären, heterotopen Ossifikationen nach Implantation von Hüfttotalendoprothesen. doi:10.1055/s-2008-1040220 8506732
39 Gregoritch SJ, Chadha M, Pelligrini VD, Rubin P, Kantorowitz DA. Randomized trial comparing preoperative versus postoperative irradiation for prevention of heterotopic ossification following prosthetic total hip replacement: preliminary results. Int J Radiat Oncol Biol Phys. Aug 30 1994;30(1):55–62. doi:10.1016/0360-3016(94)90519-3 8083129
40 Haas ML, Kennedy AS, Copeland CC, Ames JW, Scarboro M, Slawson RG. Utility of radiation in the prevention of heterotopic ossification following repair of traumatic acetabular fracture. Int J Radiat Oncol Biol Phys. Sep 1 1999;45(2):461–6. doi:10.1016/s0360-3016(99)00191-1 10487572
41 Han CD, Choi CH, Suh CO. Prevention of heterotopic bone formation after total hip arthroplasty using 600 rad in single dose in high risk patient. Yonsei Med J. Apr 1997;38(2):96–100. doi:10.3349/ymj.1997.38.2.96 9175487
42 Hanna M, Farid YR, Finn HA. Low-dose preoperative unshielded radiation is effective in heterotopic ossification prophylaxis and does not affect porous fixation in total hip arthroplasty at 2 years minimum follow-up: A radiographic study. J Am Acad Orthop Surg. Mar 1 2022;30(5):223–228. doi:10.5435/jaaos-d-21-00113 35133992
43 Hashem R, Tanzer M, Rene N, Evans M, Souhami L. Postoperative radiation therapy after hip replacement in high-risk patients for development of heterotopic bone formation. Cancer Radiother. Jul 2011;15(4):261–4. doi:10.1016/j.canrad.2010.10.003 21292525
44 Healy WL, Lo TC, Covall DJ, Pfeifer BA, Wasilewski SA. Single-dose radiation therapy for prevention of heterotopic ossification after total hip arthroplasty. J Arthroplasty. Dec 1990;5(4):369–75. doi:10.1016/s0883-5403(08)80097-6 2127057
45 Healy WL, Lo TC, DeSimone AA, Rask B, Pfeifer BA. Single-dose irradiation for the prevention of heterotopic ossification after total hip arthroplasty. A comparison of doses of five hundred and fifty and seven hundred centigray. J Bone Joint Surg Am. Apr 1995;77(4):590–5. doi:10.2106/00004623-199504000-00013 7713977
46 Hedley AK, Mead LP, Hendren DH. The prevention of heterotopic bone formation following total hip arthroplasty using 600 rad in a single dose. J Arthroplasty. Dec 1989;4(4):319–25. doi:10.1016/s0883-5403(89)80033-6 2516119
47 Heyd R, Buhleier T, Zamboglou N. Radiation therapy for prevention of heterotopic ossification about the elbow. Strahlenther Onkol. Aug 2009;185(8):506–11. doi:10.1007/s00066-009-1968-x 19652933
48 Heyd R, Schopohl B, Kirchner J, Böttcher HD. [Preoperative radiotherapy for prevention of heterotopic ossifications after hip endoprosthesis]. Aktuelle Radiol. Sep 1997;7(5):270–3. Präoperative Radiotherapie (RT) zur Prophylaxe heterotoper Ossifikationen (HO) nach Hüftendoprothese.9410001
49 Heyd R, Strassmann G, Kirchner J, Schopohl B, Böttcher HD. [Postoperative radiotherapy in the prevention of heterotopic ossification after endoprosthetic hip joint replacement]. Strahlenther Onkol. Oct 1996;172(10):543–52. Postoperative Strahlentherapie zur Prävention heterotoper Ossifikationen nach endoprothetischem Huftgelenkersatz.8966671
50 Heyd R, Tselis N, Ackermann H, Röddiger SJ, Zamboglou N. [Functional outcome after megavoltage irradiation for heel spurs]. Strahlenther Onkol. Dec 2006;182(12):733–9. Funktionelle Ergebnisse nach Megavoltbestrahlung beim Fersensporn. doi:10.1007/s00066-006-1569-x 17149581
51 Honore T, Bonan I, Salga M, . Effectiveness of radiotherapy to prevent recurrence of heterotopic ossification in patients with spinal cord injury and traumatic head injury: A retrospective case-controlled study. J Rehabil Med. May 31 2020;52(5):jrm00066. doi:10.2340/16501977-2692 32421202
52 Jasty M, Schutzer S, Tepper J, Willett C, Stracher MA, Harris WH. Radiation-blocking shields to localize periarticular radiation precisely for prevention of heterotopic bone formation around uncemented total hip arthroplasties. Clin Orthop Relat Res. Aug 1990;(257):138–45.
53 Jensen AW, Viozzi CF, Foote RL. Long-term results of radiation prophylaxis for heterotopic ossification in the temporomandibular joint. J Oral Maxillofac Surg. May 2010;68(5):1100–5. doi:10.1016/j.joms.2009.12.018 20185221
54 Jiang J, Fang T, Chen L, Chen Y, Sun B. [Efficacy and prognostic factors of preoperative radiation therapy of elbow arthrolysis]. Zhonghua Yi Xue Za Zhi. Apr 8 2014;94(13):1003–5.24851688
55 Kandaz M, Aynaci Ö, Canyılmaz E, Aynacı O, Yoney A. Radiotherapy results for heterotopic ossification prophylaxis: single center experience from eastern Black Sea Region of Turkey. UHOD-ULUSLARARASI HEMATOLOJI-ONKOLOJI DERGISI. 2019;29(2)
56 Kennedy WF, Gruen TA, Chessin H, Gasparini G, Thompson W. Radiation therapy to prevent heterotopic ossification after cementless total hip arthroplasty. Clin Orthop Relat Res. Jan 1991;(262):185–91.
57 Kersh R, Constable W, Spaulding C, Eisert D, Selby J, Cook D. Low-dose radiotherapy for control of heterotopic bone formation. Appl Radiol. 1989;10:31–34.
58 Kitchen J, Hartley B, Seligson D. Heterotopic ossification prophylaxis after acetabular fracture fixation using a posterior approach: a retrospective study at a level 1 trauma center. Current Orthopaedic Practice. 2022:10.1097/BCO.0000000000001158.
59 Knelles D, Barthel T, Karrer A, Kraus U, Eulert J, Kölbl O. Prevention of heterotopic ossification after total hip replacement. A prospective, randomised study using acetylsalicylic acid, indomethacin and fractional or single-dose irradiation. J Bone Joint Surg Br. Jul 1997;79(4):596–602. doi:10.1302/0301-620x.79b4.6829 9250745
60 Koelbl O, Seufert J, Pohl F, . Preoperative irradiation for prevention of heterotopic ossification following prosthetic total hip replacement results of a prospective study in 462 hips. Strahlenther Onkol. Nov 2003;179(11):767–73. doi:10.1007/s00066-003-1088-y 14605747
61 Kölbl O, Flentje M, Eulert J, Barthel T, Knelles D, Kraus U. [Prospective study on the prevention of heterotopic ossification after total hip replacement. Non-steroidal anti-inflammatory agents versus radiation therapy]. Strahlenther Onkol. Dec 1997;173(12):677–82. Prospektive Studie zur Vermeidung heterotoper Ossifikationen nach Hüftgelenksersatz. Nichtsteroidales Antirheumatikum versus Strahlentherapie. doi:10.1007/bf03038450 9454352
62 Konski A, Pellegrini V, Poulter C, . Randomized trial comparing single dose versus fractionated irradiation for prevention of heterotopic bone: a preliminary report. Int J Radiat Oncol Biol Phys. May 1990;18(5):1139–42. doi:10.1016/0360-3016(90)90450-x 2112120
63 Krauss H, Maier D, Bühren V, Högel F. Development of heterotopic ossifications, blood markers and outcome after radiation therapy in spinal cord injured patients. Spinal Cord. May 2015;53(5):345–8. doi:10.1038/sc.2014.186 25420497
64 Kruser TJ, Kozak KR, Cannon DM, Platta CS, Heiner JP, Illgen RL, 2nd. Low rates of heterotopic ossification after resurfacing hip arthroplasty with use of prophylactic radiotherapy in select patients. J Arthroplasty. Aug 2012;27(7):1349–53. doi:10.1016/j.arth.2011.11.017 22245125
65 Le Duff MJ, Takamura KB, Amstutz HC. Incidence of heterotopic ossification and effects of various prophylactic methods after hip resurfacing. Bull NYU Hosp Jt Dis. 2011;69 Suppl 1:S36–41.22035483
66 Linclau L, Dokter G, Debois JM, Gutwirth P. Radiation therapy to prevent heterotopic ossification in cementless total hip arthroplasty. Acta Orthop Belg. 1994;60(2):220–4.8053324
67 Linclau L, Dokter G, Debois JM, Gutwirth P. The influence of radiation therapy on the Harris hip score in cementless total hip arthroplasty. Acta Orthop Belg. 1995;61(1):48–52.7725906
68 Liu JZ, Frisch NB, Barden RM, Rosenberg AG, Silverton CD, Galante JO. Heterotopic ossification prophylaxis after total hip arthroplasty: randomized trial of 400 vs 700 cGy. J Arthroplasty. Apr 2017;32(4):1328–1334. doi:10.1016/j.arth.2016.10.030 27884418
69 Liu XH, Jiang XY, Gong MQ, Zha YJ. [Effect of radiotherapy and indomethacin together in the prevention of recurrence of ectopic ossification around the elbow after resection]. Beijing Da Xue Xue Bao Yi Xue Ban. Apr 18 2016;48(2):230–3.27080272
70 Lo TC, Healy WL, Covall DJ, . Heterotopic bone formation after hip surgery: prevention with single-dose postoperative hip irradiation. Radiology. Sep 1988;168(3):851–4. doi:10.1148/radiology.168.3.3136510 3136510
71 Lonardi F, Gioga G, Coeli M, . Preoperative, single-fraction irradiation for prophylaxis of heterotopic ossification after total hip arthroplasty. Int Orthop. 2001;25(6):371–4. doi:10.1007/s002640100281 11820444
72 Macheras GA, Lepetsos P, Leonidou A, Anastasopoulos PP, Galanakos SP, Tsiridis E. Results from the surgical resection of severe heterotopic ossification of the hip: a case series of 26 patients. Eur J Orthop Surg Traumatol. Dec 2017;27(8):1097–1102. doi:10.1007/s00590-017-1980-2 28589499
73 MacLennan I, Keys HM, Evarts CM, Rubin P. Usefulness of postoperative hip irradiation in the prevention of heterotopic bone formation in a high risk group of patients. Int J Radiat Oncol Biol Phys. Jan 1984;10(1):49–53. doi:10.1016/0360-3016(84)90411-5
74 Maier D. [Heterotopic ossification spinal cord injury. Management through early diagnosis and therapy]. Orthopade. Feb 2005;34(2):120, 122–7. Heterotope Ossifikationen bei Querschnittlähmung. Management zur Frühdiagnose und Therapie. doi:10.1007/s00132-004-0754-9 15666138
75 Maloney WJ, Jasty M, Willett C, Mulroy RD, Jr., Harris WH. Prophylaxis for heterotopic bone formation after total hip arthroplasty using low-dose radiation in high-risk patients. Clin Orthop Relat Res. Jul 1992;(280):230–4.1611750
76 Martini F, Sell S, Reize P, Jani R, Kusswetter W. Perioperative side-effects of preventative measures against heterotopic-oddification diclofenac versus irradiation. Aktuelle Rheumatologie. 1995;20(2):61–65.
77 Mishra MV, Austin L, Parvizi J, Ramsey M, Showalter TN. Safety and efficacy of radiation therapy as secondary prophylaxis for heterotopic ossification of non-hip joints. J Med Imaging Radiat Oncol. Jun 2011;55(3):333–6. doi:10.1111/j.1754-9485.2011.02275.x 21696569
78 Miszczyk L, Spindel J, Maciejewski B, . [Radiotherapy as prevention of heterotopic ossification--preliminary results]. Przegl Lek. 2004;61(2):61–4. Zastosowanie radioterapii jako metody zapobiegajacej kostnieniu pozakostnemu--doniesienie wstepne.15230142
79 Moed BR, Letournel E. Low-dose irradiation and indomethacin prevent heterotopic ossification after acetabular fracture surgery. J Bone Joint Surg Br. Nov 1994;76(6):895–900.7983114
80 Mohamed R, Iqbal A, Elawadi AA. Fifteen years’ experience of radiation therapy for resected advanced heterotopic ossification following motor vehicle accidents: outcome and side effects. J Egypt Natl Canc Inst. Nov 21 2022;34(1):48. doi:10.1186/s43046-022-00149-w 36404362
81 Mourad WF, Packianathan S, Ma JK, . Computerized tomography-based radiotherapy improves heterotopic ossification outcomes. Bone. Nov 2013;57(1):132–6. doi:10.1016/j.bone.2013.08.001 23938292
82 Mourad WF, Packianathan S, Shourbaji RA, . The impact of body mass index on heterotopic ossification. Int J Radiat Oncol Biol Phys. Apr 1 2012;82(5):e831–6. doi:10.1016/j.ijrobp.2011.11.033 22365623
83 Mourad WF, Packianathan S, Shourbaji RA, . A prolonged time interval between trauma and prophylactic radiation therapy significantly increases the risk of heterotopic ossification. Int J Radiat Oncol Biol Phys. Mar 1 2012;82(3):e339–44. doi:10.1016/j.ijrobp.2011.06.1981 22019241
84 Mourad WF, Packianathan S, Shourbaji RA, . The influence of pregnancy on heterotopic ossification post-displaced acetabular fractures surgical repair. J Orthop Res. Jun 2013;31(6):944–8. doi:10.1002/jor.22309 23335247
85 Mourad WF, Packianathan S, Shourbaji RA, . The impact of class III (morbid) obesity on heterotopic ossification outcomes. Pract Radiat Oncol. Jul–Sep 2012;2(3):e1–e6. doi:10.1016/j.prro.2011.11.003 24674128
86 Müseler AC, Grasmücke D, Jansen O, . In-hospital outcomes following single-dose radiation therapy in the treatment of heterotopic ossification of the hip following spinal cord injury-an analysis of 444 cases. Spinal Cord. Mar 2017;55(3):244–246. doi:10.1038/sc.2016.112 27431658
87 Nasr E, Nehme R, Ghanem I, Azoury F, Nasr DN, Dagher F. [Role of radiotherapy in heterotopic ossification]. Cancer Radiother. Jan 2009;13(1):42–6. Rôle de la radiothérapie dans l’ossification hétérotopique. doi:10.1016/j.canrad.2008.06.003 18701334
88 Padgett DE, Holley KG, Cummings M, . The efficacy of 500 CentiGray radiation in the prevention of heterotopic ossification after total hip arthroplasty: a prospective, randomized, pilot study. J Arthroplasty. Sep 2003;18(6):677–86. doi:10.1016/s0883-5403(03)00265-1 14513439
89 Pakos EE, Pitouli EJ, Tsekeris PG, Papathanasopoulou V, Stafilas K, Xenakis TH. Prevention of heterotopic ossification in high-risk patients with total hip arthroplasty: the experience of a combined therapeutic protocol. Int Orthop. Apr 2006;30(2):79–83. doi:10.1007/s00264-005-0054-y 16482442
90 Pakos EE, Tsekeris PG, Paschos NK, Pitouli EJ, Motsis EK, Xenakis TA. The role of radiation dose in a combined therapeutic protocol for the prevention of heterotopic ossification after total hip replacement. J buon. Jan–Mar 2010;15(1):74–8.20414931
91 Pakos EE, Papadopoulos DV, Gelalis ID, . Is prophylaxis for heterotopic ossification with radiation therapy after THR associated with early loosening or carcinogenesis? Hip Int. Sep 2020;30(5):559–563. doi:10.1177/1120700019842724 30990093
92 Pakos EE, Stafilas KS, Politis AN, Tsekeris PG, Mitsionis G, Xenakis TA. Heterotopic ossification after total hip arthroplasty (THA) in congenital hip disease: comparison of two different prophylactic protocols. Clin Transl Oncol. Feb 2009;11(2):103–8. doi:10.1007/s12094-009-0322-1 19211376
93 Pakos EE, Stafilas KS, Tsekeris PG, Politis AN, Mitsionis G, Xenakis TA. Combined radiotherapy and indomethacin for the prevention of heterotopic ossification after total hip arthroplasty. Strahlenther Onkol. Aug 2009;185(8):500–5. doi:10.1007/s00066-009-1954-3 19652932
94 Parkinson JR, Evarts CM, Hubbard LF. Radiation therapy in the prevention of heterotopic ossification after total hip arthroplasty. Hip. 1982:211–27.
95 Pellegrini VD, Jr., Gregoritch SJ. Preoperative irradiation for prevention of heterotopic ossification following total hip arthroplasty. J Bone Joint Surg Am. Jun 1996;78(6):870–81. doi:10.2106/00004623-199606000-00010 8666605
96 Piatek S, Westphal T, Arbter D, Winckler S. [Value of a combined ossification prophylaxis with indomethacin and radiotherapy for acetabular fractures]. Unfallchirurg. Jul 2006;109(7):556–62. Wertigkeit einer kombinierten Ossifikationsprophylaxe mit Indometacin und Bestrahlung bei Azetabulumfrakturen. doi:10.1007/s00113-006-1083-8 16786326
97 Pohl F, Seufert J, Tauscher A, . The influence of heterotopic ossification on functional status of hip joint following total hip arthroplasty. Strahlenther Onkol. Aug 2005;181(8):529–33. doi:10.1007/s00066-005-1352-4 16044221
98 Rashid RH, Qadir I, Ahmed W, Umer M. Prophylaxis against heterotopic ossification after elbow and acetabular fractures - Do we really need it. J Pak Med Assoc. Nov 2015;65(11 Suppl 3):S87–90.26878545
99 Robinson CG, Polster JM, Reddy CA, . Postoperative single-fraction radiation for prevention of heterotopic ossification of the elbow. Int J Radiat Oncol Biol Phys. Aug 1 2010;77(5):1493–9. doi:10.1016/j.ijrobp.2009.06.072 20637977
100 Rudicel S. [Para-articular (ectopic or heterotopic) ossification following total hip prosthesis]. Orthopade. Feb 1985;14(1):54–7. Paraartikuläre (ektopische oder heterotope) Ossifikationen nach Hüfttotalprothese.3921900 Ruo Redda MG, De Colle C, Bianco L, . Heterotopic ossifications: role of radiotherapy as prophylactic treatment. Radiol Med. Jun 2018;123(6):463–468. doi:10.1007/s11547-018-0853-z 29397526
101 Sarafis KA, Karatzas GD, Yotis CL. Ankylosed hips caused by heterotopic ossification after traumatic brain injury: a difficult problem. J Trauma. Jan 1999;46(1):104–9. doi:10.1097/00005373-199901000-00017 9932691
102 Sauer R, Seegenschmiedt MH, Goldmann A, Beck H, Andreas P. [Prevention of periarticular ossification following endoprosthetic hip replacement using postoperative irradiation]. Strahlenther Onkol. Feb 1992;168(2):89–99. Prophylaxe periartikulärer Verknöcherungen nach endoprothetischem Hüftgelenksersatz durch postoperative Bestrahlung.1542851
103 Sautter-Bihl ML, Hültenschmidt B, Liebermeister E, Nanassy A. Fractionated and single-dose radiotherapy for heterotopic bone formation in patients with spinal cord injury. A phase-I/II study. Strahlenther Onkol. Apr 2001;177(4):200–5. doi:10.1007/pl00002399 11370555
104 Sautter-Bihl ML, Liebermeister E, Heinze HG, Nanassy A, Stoltze D. [The radiotherapy of heterotopic ossifications in paraplegics. The preliminary results]. Strahlenther Onkol. Aug 1995;171(8):454–9. Strahlentherapie heterotoper Ossifikationen bei Querschnittsgelähmten. Präliminäre Ergebnisse.7652668
105 Sautter-Bihl ML, Liebermeister E, Nanassy A. Radiotherapy as a local treatment option for heterotopic ossifications in patients with spinal cord injury. Spinal Cord. Jan 2000;38(1):33–6. doi:10.1038/sj.sc.3100847 10762195
106 Schai P, Brunner R, Morscher E, Schubert KH. Prevention of heterotopic ossification in hip arthroplasties by means of an early single-dose radiotherapy (6 Gy). Arch Orthop Trauma Surg. 1995;114(3):153–8. doi:10.1007/bf00443389 7619636
107 Schai P, Brunner R, Morscher E, Schubert KH. Prevention of heterotopic ossification in hip arthroplasties by means of an early single-dose radiotherapy (6 Gy). Arch Orthop Trauma Surg. 1995;114(3):153–8. doi:10.1007/bf00443389 7619636
108 Seegenschmiedt MH, Goldmann AR, Wölfel R, Hohmann D, Beck H, Sauer R. Prevention of heterotopic ossification (HO) after total hip replacement: randomized high versus low dose radiotherapy. Radiother Oncol. Mar 1993;26(3):271–4. doi:10.1016/0167-8140(93)90270-i 8316658
109 Seegenschmiedt MH, Keilholz L, Martus P, . Prevention of heterotopic ossification about the hip: final results of two randomized trials in 410 patients using either preoperative or postoperative radiation therapy. Int J Radiat Oncol Biol Phys. Aug 1 1997;39(1):161–71. doi:10.1016/s0360-3016(97)00285-x 9300751
110 Seegenschmiedt MH, Makoski HB, Micke O. Radiation prophylaxis for heterotopic ossification about the hip joint--a multicenter study. Int J Radiat Oncol Biol Phys. Nov 1 2001;51(3):756–65. doi:10.1016/s0360-3016(01)01640-6 11697322
111 Seegenschmiedt MH, Martus P, Goldmann AR, Wölfel R, Keilholz L, Sauer R. [Pre- and postoperative radiotherapy to prevent heterotopic ossification of the hip joint]. Strahlenther Onkol. May 1994;170(5):281–91. Prä- und postoperative Radiotherapie zur Prophylaxe von heterotopen Ossifikationen am Hüftgelenk.8197551
112 Seegenschmiedt MH, Martus P, Goldmann AR, Wölfel R, Keilholz L, Sauer R. Preoperative versus postoperative radiotherapy for prevention of heterotopic ossification (HO): first results of a randomized trial in high-risk patients. Int J Radiat Oncol Biol Phys. Aug 30 1994;30(1):63–73. doi:10.1016/0360-3016(94)90520-7 8083130
113 Sell S, Jany R, Kremling E, Esenwein S, Gaissmaier C, Küsswetter W. [Prevention of heterotopic ossification following cementless hip replacement using 5 × 2 Gy fractionated irradiation. A prospective study]. Z Orthop Ihre Grenzgeb. Jul–Aug 1996;134(4):375–80. Prävention heterotoper Ossifikationen nach zementfreiem Hüftgelenksersatz durch fraktionierte Radiatio mit 5 × 2 Gy. Eine prospektive Studie. doi:10.1055/s-2008-1039778 8928569
114 Slawson RG, Poka A, Bathon H, Salazar OM, Bromback RJ, Burgess AR. The role of post-operative radiation in the prevention of heterotopic ossification in patients with post-traumatic acetabular fracture. Int J Radiat Oncol Biol Phys. Sep 1989;17(3):669–72. doi:10.1016/0360-3016(89)90122-3 2506160
115 Spry NA, Dally MJ, Benjamin B, Chapman P, Morum P, Christie DR. Heterotopic bone formation affecting the hip joint is preventable in high risk patients by post-operative radiation. Australas Radiol. Nov 1995;39(4):379–83. doi:10.1111/j.1440-1673.1995.tb00316.x 8561714
116 Starr AJ, Watson JT, Reinert CM, . Complications following the “T extensile" approach: a modified extensile approach for acetabular fracture surgery-report of forty-three patients. J Orthop Trauma. Sep 2002;16(8):535–42. doi:10.1097/00005131-200209000-00001 12352561
117 Stein DA, Patel R, Egol KA, Kaplan FT, Tejwani NC, Koval KJ. Prevention of heterotopic ossification at the elbow following trauma using radiation therapy. Bull Hosp Jt Dis. 2003;61(3–4):151–4.15156818
118 Strauss JB, Wysocki RW, Shah A, . Radiation therapy for heterotopic ossification prophylaxis afer high-risk elbow surgery. Am J Orthop (Belle Mead NJ). Aug 2011;40(8):400–5.22016869
119 Sylvester JE, Blount LH, Selch MT. Technical considerations in the use of prophylactic radiation therapy to prevent heterotopic bone formation. Semin Arthroplasty. Jul 1992;3(3):167–71.10147775
120 Sylvester JE, Greenberg P, Selch MT, Thomas BJ, Amstutz H. The use of postoperative irradiation for the prevention of heterotopic bone formation after total hip replacement. Int J Radiat Oncol Biol Phys. Mar 1988;14(3):471–6. doi:10.1016/0360-3016(88)90262-3 3343154
121 Tabaie SA, Dombrowski J, Moed BR. Does prophylactic irradiation port size affect the extent of heterotopic ossification after acetabular fracture surgery? A pilot study. Current Orthopaedic Practice. 2014;25(6):592–596.
122 Wahl B, Grasshoff H, Meinecke I, Neumann HW. [Clinical and radiological results of surgical removal of periarticular ossifications after hip prosthesis implantation]. Unfallchirurg. Jun 2002;105(6):523–6. Klinische und radiologische Ergebnisse der operativen Entfernung von periartikulären Ossifikationen nach Hüftendoprothese. doi:10.1007/s00113-001-0381-4 12132191
123 Warren SB, Brooker AF, Jr. Excision of heterotopic bone followed by irradiation after total hip arthroplasty. J Bone Joint Surg Am. Feb 1992;74(2):201–10.1541614
124 Weng HK, Wu PK, Chen CF, . Total hip arthroplasty for patients who have ankylosing spondylitis: Is postoperative irradiation required for prophylaxis of heterotopic ossification? J Arthroplasty. Oct 2015;30(10):1752–6. doi:10.1016/j.arth.2015.04.022 25980776
125 Wey J, DiPasquale D, Levitt L, Quitkin H. Operative treatment of acetabular fractures through the extensile Henry approach. J Trauma. Feb 1999;46(2):255–60. doi:10.1097/00005373-199902000-00010 10029030
126 Wingo T, Shankar DS, Essilfie AA, Youm T. Endoscopic Excision of Hip Heterotopic Ossification, Plus Indomethacin and Radiation, Is Effective in Treating and Preventing Recurrence. Arthrosc Sports Med Rehabil. Feb 2023;5(1):e165–e169. doi:10.1016/j.asmr.2022.11.008 36866299
127 Wölfel R, Seegenschmiedt MH, Günther K, Sauer R, Beck H, Hohmann D. [Prevention of para-articular ossifications after endoprosthetic hip joint replacement by postoperative irradiation]. Chirurg. Nov 1994;65(11):1015–22. Prophylaxe paraarticulärer Ossifikationen nach endoprothetischem Hüftgelenkersatz durch postoperative Bestrahlung.7821060
128 Wu FF, Gao HL, Huang S, . [NSAIDs combined with radiotherapy to prevent heterotopic ossification after total hip arthroplasty]. Zhongguo Gu Shang. Jun 25 2018;31(6):538–542. doi:10.3969/j.issn.1003-0034.2018.06.011 29945410
129 Wu XB, Yang MH, Zhu SW, . Surgical resection of severe heterotopic ossification after open reduction and internal fixation of acetabular fractures: a case series of 18 patients. Injury. Oct 2014;45(10):1604–10. doi:10.1016/j.injury.2014.05.018 24917211

### Keloids: 138 Exclusions

1 Abdus-Salam AA, Orekoya AA, Jimoh MA, Olabumuyi AA. Radiotherapy treatment of keloids in Ibadan. J West Afr Coll Surg. Oct–Dec 2016;6(4):104–116.29181367
2 Ahmad M, Ahmad H, Khattak MR, . Postoperative single versus multiple fractions high-dose rate iridium-192 surface mould brachytherapy for keloid treatment: a comparative study. Journal of Radiotherapy in Practice. 2018;17(1):60–65.
3 Akita S, Akino K, Yakabe A, . Combined surgical excision and radiation therapy for keloid treatment. J Craniofac Surg. Sep 2007;18(5):1164–9. doi:10.1097/scs.0b013e3180de62a1 17912105
4 Anderson EM, David J, Phillips T, . Interstitial high-dose-rate brachytherapy in the treatment of keloids: Moving toward a volumetric approach. Brachytherapy. Jan–Feb 2021;20(1):185–188. doi:10.1016/j.brachy.2020.07.008 32811762
5 Arima J, Dohi T, Kuribayashi S, Akaishi S, Ogawa R. Z-plasty and postoperative radiotherapy for anterior chest wall keloids: An analysis of 141 patients. Plast Reconstr Surg Glob Open. Mar 2019;7(3):e2177. doi:10.1097/gox.0000000000002177 31044131
6 Arnault JP, Peiffert D, Latarche C, Chassagne JF, Barbaud A, Schmutz JL. Keloids treated with postoperative Iridium 192* brachytherapy: a retrospective study. J Eur Acad Dermatol Venereol. Jul 2009;23(7):807–13. doi:10.1111/j.1468-3083.2009.03190.x 19470053
7 Arneja JS, Singh GB, Dolynchuk KN, Murray KA, Rozzelle AA, Jones KD. Treatment of recurrent earlobe keloids with surgery and high-dose-rate brachytherapy. Plast Reconstr Surg. Jan 2008;121(1):95–99. doi:10.1097/01.prs.0000293755.64918.22 18176210
8 Bautista Hernandez Y, Villavicencio Queijero MA, Quezada Bautista AA, Vazquez Tinajero A. Surface brachytherapy in the treatment of keloid scars in Mexico. Rep Pract Oncol Radiother. Jan–Feb 2020;25(1):133–138. doi:10.1016/j.rpor.2019.11.002 31920465
9 Bennett KG, Kung TA, Hayman JA, Brown DL. Treatment of keloids with excision and adjuvant radiation: A single center experience and review of the literature. Ann Plast Surg. Feb 2017;78(2):157–161. doi:10.1097/sap.0000000000000903 27775986
10 Berman B, Nestor MS, Gold MH, Goldberg DJ, Weiss ET, Raymond I. A retrospective registry study evaluating the long-term efficacy and safety of superficial radiation therapy following excision of keloid scars. J Clin Aesthet Dermatol. Oct 2020;13(10):12–16.
11 Bertiere MN, Jousset C, Marin JL, Baux S. [Value of interstitial irradiation of keloid scars by Iridium 192. Apropos of 46 cases]. Ann Chir Plast Esthet. 1990;35(1):27–30. Intérêt de l’irradiation interstitielle des cicatrices chéloïdes par Iridium 192. A propos de 46 cas.1693824
12 Bhusari P, Shukla J, Kumar M, . Noninvasive treatment of keloid using customized Re-188 skin patch. Dermatol Ther. Sep 2017;30(5)doi:10.1111/dth.12515
13 Bijlard E, Verduijn GM, Harmeling JX, . Optimal high-dose-rate brachytherapy fractionation scheme after keloid excision: A retrospective multicenter comparison of recurrence rates and complications. Int J Radiat Oncol Biol Phys. Mar 1 2018;100(3):679–686. doi:10.1016/j.ijrobp.2017.10.044 29249529
14 Bischof M, Krempien R, Debus J, Treiber M. Postoperative electron beam radiotherapy for keloids: objective findings and patient satisfaction in self-assessment. Int J Dermatol. Sep 2007;46(9):971–5. doi:10.1111/j.1365-4632.2007.03326.x 17822505
15 Caccialanza M, Dal Pozzo V, Piccinno R, Beretta M, Gnecchi L. Postoperative radiotherapy of earlobe keloids. Giornale italiano di dermatologia e venereologia. 1998;133(6):399–404.
16 Caccialanza M, Piccinno R, Schiera A. Postoperative radiotherapy of keloids: a twenty-year experience. Eur J Dermatol. Jan–Feb 2002;12(1):58–62.11809597
17 Capel AV, Palop JV, Olivé AP, Fernández AS-R. Adjuvance in refractory keloids using electron beams with a spoiler: Recent results. Reports of Practical Oncology and Radiotherapy. 2015;20(1):43–49.25535584
18 Carvajal CC, Ibarra CM, Arbulo DL, Russo MN, Solé CP. Postoperative radiotherapy in the management of keloids. Ecancermedicalscience. 2016;10:690. doi:10.3332/ecancer.2016.690 27994646
19 Chaudhry MR, Akhtar S, Duvalsaint F, Garner L, Lucente FE. Ear lobe keloids, surgical excision followed by radiation therapy: a 10-year experience. Ear Nose Throat J. Oct 1994;73(10):779–81.7805600
20 Chen F, Kuo YR, Huang CJ, Tang JY, Chiang CH, Huang MY. Lesion site is the key prognostic factor for keloid patients receiving surgery with adjuvant radiotherapy. Ann Plast Surg. Dec 1 2022;89(6):626–630. doi:10.1097/sap.0000000000003315 36416688
21 Clavere P, Bedane C, Bonnetblanc JM, Bonnafoux-Clavere A, Rousseau J. Postoperative interstitial radiotherapy of keloids by iridium 192: a retrospective study of 46 treated scars. Dermatology. 1997;195(4):349–52. doi:10.1159/000245986 9529555
22 De Cicco L, Vischioni B, Vavassori A, . Postoperative management of keloids: low-dose-rate and high-dose-rate brachytherapy. Brachytherapy. Sep–Oct 2014;13(5):508–13. doi:10.1016/j.brachy.2014.01.005 24556345
23 De Lorenzi F, Tielemans HJ, van der Hulst RR, . Is the treatment of keloid scars still a challenge in 2006? Ann Plast Surg. Feb 2007;58(2):186–92. doi:10.1097/01.sap.0000237761.52586.f9 17245147
24 Deng K, Xiao H, Liu X, Ogawa R, Xu X, Liu Y. Strontium-90 brachytherapy following intralesional triamcinolone and 5-fluorouracil injections for keloid treatment: A randomized controlled trial. PLoS One. 2021;16(3):e0248799. doi:10.1371/journal.pone.0248799 33755674
25 Dohi T, Kuribayashi S, Aoki M, Tosa M, Akaishi S, Ogawa R. Combination therapy composed of surgery, postoperative radiotherapy, and wound self-management for umbilical keloids. Plast Reconstr Surg Glob Open. Oct 2020;8(10):e3181. doi:10.1097/gox.0000000000003181 33173693
26 Dohi T, Kuribayashi S, Tosa M, Aoki M, Akaishi S, Ogawa R. Z-plasty and postoperative radiotherapy for upper-arm keloids: An analysis of 38 patients. Plast Reconstr Surg Glob Open. Nov 2019;7(11):e2496. doi:10.1097/gox.0000000000002496 31942294
27 Doornbos JF, Stoffel TJ, Hass AC, . The role of kilovoltage irradiation in the treatment of keloids. Int J Radiat Oncol Biol Phys. Apr 1990;18(4):833–9. doi:10.1016/0360-3016(90)90405-9 2108939
28 Duan Q, Liu J, Luo Z, Hu C. Postoperative brachytherapy and electron beam irradiation for keloids: A single institution retrospective analysis. Mol Clin Oncol. May 2015;3(3):550–554. doi:10.3892/mco.2015.498 26137265
29 Durosinmi-Etti FA, Olasinde TA, Solarin EO. A short course postoperative radiotherapy regime for keloid scars in Nigeria. West Afr J Med. Jan–Mar 1994;13(1):17–9.8080824
30 Eaton DJ, Barber E, Ferguson L, Mark Simpson G, Collis CH. Radiotherapy treatment of keloid scars with a kilovoltage X-ray parallel pair. Radiother Oncol. Mar 2012;102(3):421–3. doi:10.1016/j.radonc.2011.08.002 21889225
31 Enhamre A, Hammar H. Treatment of keloids with excision and postoperative X-ray irradiation. Dermatologica. 1983;167(2):90–3. doi:10.1159/000249754 6628805
32 Escarmant P, Zimmermann S, Amar A, . The treatment of 783 keloid scars by iridium 192 interstitial irradiation after surgical excision. Int J Radiat Oncol Biol Phys. May 20 1993;26(2):245–51. doi:10.1016/0360-3016(93)90204-9 8491682
33 Fierro-Arias L, Peyro-Quiñones E, Peniche-Castellanos A, Ponce-Olivera RM. Superficial radiotherapy in Dermatology. Thirty-years experience in the Hospital General de Mexico Dr. Eduardo Liceaga. Dermatología Revista Mexicana. 2015;59(3):195–200.
34 Fraunholz IB, Gerstenhauer A, Böttcher HD. Results of postoperative (90)Sr radiotherapy of keloids in view of patients’ subjective assessment. Strahlenther Onkol. Nov 2005;181(11):724–9. doi:10.1007/s00066-005-1411-x 16254708
35 Furtado F, Hochman B, Ferreira LM. Evaluating keloid recurrence after surgical excision with prospective longitudinal scar assessment scales. J Plast Reconstr Aesthet Surg. Jul 2012;65(7):e175–81. doi:10.1016/j.bjps.2012.02.005 22386498
36 Guix B, Henríquez I, Andrés A, Finestres F, Tello JI, Martínez A. Treatment of keloids by high-dose-rate brachytherapy: A seven-year study. Int J Radiat Oncol Biol Phys. May 1 2001;50(1):167–72. doi:10.1016/s0360-3016(00)01563-7 11316560
37 Ha B, Kim SJ, Lee YJ, Im S, Park TH. Early outcomes of complete excision followed by immediate postoperative single fractional 10 Gy for anterior chest keloids: A preliminary results. Int Wound J. May 2023;20(5):1418–1425. doi:10.1111/iwj.13996 36324174
38 Hafkamp CJH, Lapid O, Dávila Fajardo R, . Postoperative single-dose interstitial high-dose-rate brachytherapy in therapy-resistant keloids. Brachytherapy. Mar–Apr 2017;16(2):415–420. doi:10.1016/j.brachy.2016.12.009 28139418
39 Han CM, Shao HW, He XJ, Wang LC. [Postoperative electron beam irradiation therapy for keloid:a follow-up study of 48 patients]. Zhonghua Wai Ke Za Zhi. Mar 7 2004;42(5):288–90.15062019
40 Handl-Zeller L, Hohenberg G. [Postoperative prevention of hypertrophic scars and keloids using radiotherapy]. Hautarzt. Mar 1990;41(3):146–8. Postoperative Prophylaxe hypertropher Narben und Keloide mittels Strahlentherapie.2345099
41 Hao Y, Liang Z, Liu H, . A nomogram with the keloid activity assessment acale for predicting the recurrence of chest keloid after surgery and radiotherapy. Aesthetic Plast Surg. Apr 2023;47(2):872–879. doi:10.1007/s00266-022-03187-w 36414722
42 Heianna J, Iida N, Otsuka K, . Investigation of the optimal dose on postoperative radiotherapy for earlobe keloid. The Journal of JASTRO. 2004;16(1):47–51.
43 Hernandez YB, Gomez KV, Lopez AL. Treatment of benign tumours and related pathologies with radiotherapy: experience of the General Hospital of Mexico. Rep Pract Oncol Radiother. 2022;27(4):684–690. doi:10.5603/RPOR.a2022.0072 36196421
44 Hoang D, Reznik R, Orgel M, Li Q, Mirhadi A, Kulber DA. Surgical excision and adjuvant brachytherapy vs external beam radiation for the effective treatment of keloids: 10-Year Institutional Retrospective Analysis. Aesthet Surg J. Feb 2017;37(2):212–225. doi:10.1093/asj/sjw124 27553611
45 Hsueh WT, Hung KS, Chen YC, . Adjuvant radiotherapy after keloid excision: Preliminary experience in Taiwan. Ann Plast Surg. Jan 2019;82(1S Suppl 1):S39–s44. doi:10.1097/sap.0000000000001728 30461461
46 Hung YT, Lin SM, Tzeng IS, Ng CY. Optimizing surgical outcome of auricular keloid with a novel multimodal approach. Sci Rep. Mar 3 2022;12(1):3533. doi:10.1038/s41598-022-07255-8 35241718
47 Hwang NH, Lee NK, Chae JH, Park SH, Yoon ES. The efficacy of CT-based conformal electron beam radiation therapy after keloid excision. Dermatol Surg. Apr 1 2022;48(4):435–440. doi:10.1097/dss.0000000000003398 35125441
48 Jiang P, Geenen M, Siebert FA, . Efficacy and the toxicity of the interstitial high-dose-rate brachytherapy in the management of recurrent keloids: 5-year outcomes. Brachytherapy. May–Jun 2018;17(3):597–600. doi:10.1016/j.brachy.2017.12.002 29305151
49 Jones ME, Ganzer CA, Bennett D, Finizio A. Surgical excision of keloids followed by in-office superficial radiation therapy: Prospective study examining clinical outcomes. Plast Reconstr Surg Glob Open. May 2019;7(5):e2212. doi:10.1097/gox.0000000000002212 31333945
50 Jones ME, Hardy C, Ridgway J. Keloid management: A retrospective case review on a new approach using surgical excision, platelet-rich plasma, and in-office superficial photon x-ray radiation therapy. Adv Skin Wound Care. Jul 2016;29(7):303–7. doi:10.1097/01.Asw.0000482993.64811.74 27300360
51 Jones ME, McLane J, Adenegan R, Lee J, Ganzer CA. Advancing keloid treatment: A novel multimodal approach to ear keloids. Dermatol Surg. Sep 2017;43(9):1164–1169. doi:10.1097/dss.0000000000001145 28375976
52 Kärcher H, Hackl A. [Post-operative radiation in scar corrections in the head and neck region]. Dtsch Z Mund Kiefer Gesichtschir. Nov–Dec 1984;8(6):476–80. Die Nachbestrahlung bei Narbenkorrekturen im Kopf-halsbereich.6598098
53 Kim J, Lee SH. Therapeutic results and safety of postoperative radiotherapy for keloid after repeated Cesarean section in immediate postpartum period. Radiat Oncol J. Jun 2012;30(2):49–52. doi:10.3857/roj.2012.30.2.49 22984682
54 Kim K, Son D, Kim J. Radiation therapy following total keloidectomy: A retrospective study over 11 Years. Arch Plast Surg. Sep 2015;42(5):588–95. doi:10.5999/aps.2015.42.5.588 26430630
55 Klumpar DI, Murray JC, Anscher M. Keloids treated with excision followed by radiation therapy. J Am Acad Dermatol. Aug 1994;31(2 Pt 1):225–31. doi:10.1016/s0190-9622(94)70152-0 8040405
56 Kovalic JJ, Perez CA. Radiation therapy following keloidectomy: a 20-year experience. Int J Radiat Oncol Biol Phys. Jul 1989;17(1):77–80. doi:10.1016/0360-3016(89)90373-8 2745211
57 Kuribayashi S, Miyashita T, Ozawa Y, . Post-keloidectomy irradiation using high-dose-rate superficial brachytherapy. J Radiat Res. 2011;52(3):365–8. doi:10.1269/jrr.10159 21490411
58 Latini C, Onesti M, Spalvieri C, Barile A, Scuderi N. Regressive vicariation of pathologic hypertrophical scars with antihomotoxic therapy. Biologische Medizin. 1999;28:11–15.
59 Lee SY, Park J. Postoperative electron beam radiotherapy for keloids: treatment outcome and factors associated with occurrence and recurrence. Ann Dermatol. Feb 2015;27(1):53–8. doi:10.5021/ad.2015.27.1.53 25673932
60 Levy DS, Salter MM, Roth RE. Postoperative irradiation in the prevention of keloids. AJR Am J Roentgenol. Sep 1976;127(3):509–10. doi:10.2214/ajr.127.3.509 183542
61 Li L, Yuan C, Zhang X, Wang B, Yan Y. Superficial X-ray-induced hyperpigmentation in postoperative keloid radiotherapy: A study of 70 keloids to identify clinical features and risk factors. J Cosmet Dermatol. Sep 2021;20(9):2880–2886. doi:10.1111/jocd.14308 34153161
62 Li PC, Jia CY, Li YM, . [Clinical efficacy of keloids treated by surgical ablation and immediate postoperative adjuvant radiotherapy]. Zhonghua Yi Xue Za Zhi. Dec 6 2011;91(45):3223–4.22333109
63 Li W, Wang Y, Wang X, Liu Z. A keloid edge precut, preradiotherapy method in large keloid skin graft treatment. Dermatol Surg. Jan 2014;40(1):52–7. doi:10.1111/dsu.12374 24237454
64 Liang C, Chuan C, Xiaoge L, Dongyun Y, Shirong L. Surgery and follow-up care for auricular keloid: a report of 156 cases. Journal of Medical Colleges of PLA. 2013;28(2):107–112.
65 Lin YF, Shueng PW, Roan TL, . Tomotherapy as an alternative irradiative treatment for complicated keloids. J Clin Med. Nov 20 2020;9(11)doi:10.3390/jcm9113732
66 Lindsey WH, Davis PT. Facial keloids. A 15-year experience. Arch Otolaryngol Head Neck Surg. Apr 1997;123(4):397–400. doi:10.1001/archotol.1997.01900040031005 9109787
67 Litoux P, Pannier M, Stalder JF. [Treatment of keloid]. Ann Dermatol Venereol. 1986;113(9):875–6. Traitement des chéloïdes.3827094
68 Liu CL, Yuan ZY. Retrospective study of immediate postoperative electron radiotherapy for therapy-resistant earlobe keloids. Arch Dermatol Res. Aug 2019;311(6):469–475. doi:10.1007/s00403-019-01922-z 31041525
69 Liu S, Liang W, Song K, Wang Y. Keloid skin flap retention and resurfacing in facial keloid treatment. Aesthetic Plast Surg. Feb 2018;42(1):304–309. doi:10.1007/s00266-017-0949-1 28791472
70 Liu X, Wang H, Cen Y, Li Z. [Synthetic therapy for keloid in aural region]. Zhongguo Xiu Fu Chong Jian Wai Ke Za Zhi. Jan 2008;22(1):56–8.18361239
71 Liu Y, Xiao H, Liu X, . [Effectiveness of internal mammary artery perforator propeller flap repair combined with radiotherapy for chest keloid in female patients]. Zhongguo Xiu Fu Chong Jian Wai Ke Za Zhi. Sep 15 2018;32(9):1196–1200. doi:10.7507/1002-1892.201803004 30129345
72 Long X, Wang XJ, Wang YB, Li WB, Sun XS. [An individualized approach combining local flaps with radiotherapy for the treatment of auricle keloid]. Zhongguo Yi Xue Ke Xue Yuan Xue Bao. Apr 2013;35(2):213–6. doi:10.3881/j.issn.1000-503X.2013.02.015 23643012
73 Long X, Zhang M, Wang Y, Zhao R, Wang Y, Wang X. Algorithm of chest wall keloid treatment. Medicine. 2016;95(35)
74 Lyu A, Xu E, Wang Q. A retrospective analysis of surgical resection of large ear keloids. Australas J Dermatol. Feb 2019;60(1):29–32. doi:10.1111/ajd.12872 29962005
75 Ma QY, Yang YT, Chen ZA, . Laser combined with radiotherapy for keloid treatment: A novel and efficient comprehensive therapy with a lower recurrence rate. Plast Reconstr Surg. Dec 1 2023;152(6):1022e–1029e. doi:10.1097/prs.0000000000010376
76 Maarouf M, Schleicher U, Schmachtenberg A, Ammon J. Radiotherapy in the management of keloids. Clinical experience with electron beam irradiation and comparison with X-ray therapy. Strahlenther Onkol. Jun 2002;178(6):330–5. doi:10.1007/s00066-002-0935-6 12122789
77 Maemoto H, Iraha S, Arashiro K, Ishigami K, Ganaha F, Murayama S. Risk factors of recurrence after postoperative electron beam radiation therapy for keloid: Comparison of long-term local control rate. Rep Pract Oncol Radiother. Jul–Aug 2020;25(4):606–611. doi:10.1016/j.rpor.2020.05.001 32523428
78 Malaker K, Vijayraghavan K, Hodson I, Al Yafi T. Retrospective analysis of treatment of unresectable keloids with primary radiation over 25 years. Clin Oncol (R Coll Radiol). Jun 2004;16(4):290–8. doi:10.1016/j.clon.2004.03.005 15214654
79 Malaker K, Zaidi M, Franka MR. Treatment of earlobe keloids using the cobalt 60 teletherapy unit. Ann Plast Surg. Jun 2004;52(6):602–4. doi:10.1097/01.sap.0000095408.74866.f1 15166996
80 Margiotta E, Ramras S, Shteynberg A. Recurrence of primary and secondary keloids in a select African American and Afro-Caribbean population. Ann Plast Surg. May 1 2022;88(3 Suppl 3):S194–s196. doi:10.1097/sap.0000000000003173 35513318
81 Masoodi Z, Ahmad I, Khurram MF, Haq A. Excision, skin grafting, corticosteroids, adjuvant radiotherapy, pressure therapy, and emancipation: the ESCAPE model for successful taming of giant auricular keloids. Adv Skin Wound Care. Sep 2014;27(9):404–12. doi:10.1097/01.ASW.0000451340.59196.9d 25133342
82 Meythiaz A, De Mey A, Lejour M. Treatment of keloids by excision and postoperative radiotherapy. European Journal of Plastic Surgery. 1992;15:13–16.
83 Mitsuhashi K, Miyashita T. [Treatment of so-called keloid with excision and postoperative electron irradiation]. Nihon Ika Daigaku Zasshi. Apr 1995;62(2):186–95. doi:10.1272/jnms1923.62.186 7775655
84 Mohamed R, Elawadi AA, Al-Gendi R, Al-Mohsen S, Wani S, Wafa A. The outcome of postoperative radiation therapy following plastic surgical resection of recurrent ear keloid: a single institution experience. J Egypt Natl Canc Inst. Jan 24 2022;34(1):4. doi:10.1186/s43046-022-00105-8 35067821
85 Mohammadi AA, Mohammadian Panah M, Pakyari MR, . Surgical excision followed by low dose rate radiotherapy in the management of resistant keloids. World J Plast Surg. Jun 2013;2(2):81–6.25489509
86 Nang’ole FW, Anzala O, Ogeng’o J, Agak GW. Determinants of keloid recurrence: The Nairobi keloid recurrence scoring system; A cohort, prospective study. International Journal of Surgery Open. 2023;52:100596.
87 Narkwong L, Thirakhupt P. Postoperative radiotherapy with high dose rate iridium 192 mould for prevention of earlobe keloids. J Med Assoc Thai. Apr 2006;89(4):428–33.16696385
88 Norris JE. Superficial x-ray therapy in keloid management: a retrospective study of 24 cases and literature review. Plast Reconstr Surg. May 1995;95(6):1051–5. doi:10.1097/00006534-199505000-00015 7732115
89 Ogawa R, Akaishi S, Dohi T, Kuribayashi S, Miyashita T, Hyakusoku H. Analysis of the surgical treatments of 63 keloids on the cartilaginous part of the auricle: effectiveness of the core excision method. Plast Reconstr Surg. Mar 2015;135(3):868–875. doi:10.1097/prs.0000000000000962 25719703
90 Ogawa R, Huang C, Akaishi S, . Analysis of surgical treatments for earlobe keloids: analysis of 174 lesions in 145 patients. Plast Reconstr Surg. Nov 2013;132(5):818e–825e. doi:10.1097/PRS.0b013e3182a4c35e
91 Ogawa R, Mitsuhashi K, Hyakusoku H, Miyashita T. Postoperative electron-beam irradiation therapy for keloids and hypertrophic scars: retrospective study of 147 cases followed for more than 18 months. Plast Reconstr Surg. Feb 2003;111(2):547–53; discussion 554-5. doi:10.1097/01.Prs.0000040466.55214.35 12560675
92 Ogawa R, Miyashita T, Hyakusoku H, Akaishi S, Kuribayashi S, Tateno A. Postoperative radiation protocol for keloids and hypertrophic scars: statistical analysis of 370 sites followed for over 18 months. Ann Plast Surg. Dec 2007;59(6):688–91. doi:10.1097/SAP.0b013e3180423b32 18046154
93 Park TH. Aesthetic reconstruction of auricular keloids with a novel hemi-keystone flap. Aesthetic Plast Surg. Dec 2022;46(6):2807–2813. doi:10.1007/s00266-022-02909-4 35552478
94 Pontoriero A, Potami A, Iatì G, . Post-operative radiotherapy of keloids. A 10-years experience of kilovoltage irradiation. 2015;
95 Ragoowansi R, Cornes PG, Glees JP, Powell BW, Moss AL. Ear-lobe keloids: treatment by a protocol of surgical excision and immediate postoperative adjuvant radiotherapy. Br J Plast Surg. Sep 2001;54(6):504–8. doi:10.1054/bjps.2001.3656 11513512
96 Ragoowansi R, Cornes PG, Moss AL, Glees JP. Treatment of keloids by surgical excision and immediate postoperative single-fraction radiotherapy. Plast Reconstr Surg. May 2003;111(6):1853–9. doi:10.1097/01.Prs.0000056869.31142.De 12711944
97 Recalcati S, Caccialanza M, Piccinno R. Postoperative radiotherapy of auricular keloids: a 26-year experience. J Dermatolog Treat. Feb 2011;22(1):38–42. doi:10.3109/09546630903460278 20653486
98 Renz P, Hasan S, Gresswell S, Hajjar RT, Trombetta M, Fontanesi J. Dose effect in adjuvant radiation therapy for the treatment of resected keloids. Int J Radiat Oncol Biol Phys. Sep 1 2018;102(1):149–154. doi:10.1016/j.ijrobp.2018.05.027 29970316
99 Ribault L, Martin JP, Larroque G. [Keloid cicatrix of the face and neck. Apropos of 81 cases treated in Dakar]. Ann Chir Plast Esthet. Mar 1992;37(2):202–6. Les cicatrices chéloïdes cervico-faciales. A propos de 81 cas traités à Dakar.1456722
100 Rishi KS, Sarkar N, Kesari P, . Single institution experience of postoperative electron beam radiation therapy in the treatment of keloids. Adv Radiat Oncol. Mar–Apr 2021;6(2):100596. doi:10.1016/j.adro.2020.10.009 33732956
101 Rong L, Wu X, Hou Y, Ma X, Ye M, Bai Y. [Long-term results of postoperative electronic irradiation for 53 patients with keloids]. Zhonghua Zheng Xing Wai Ke Za Zhi. Jul 2014;30(4):270–4.25322574
102 Sakamoto T, Oya N, Shibuya K, Nagata Y, Hiraoka M. Dose-response relationship and dose optimization in radiotherapy of postoperative keloids. Radiother Oncol. May 2009;91(2):271–6. doi:10.1016/j.radonc.2008.12.018 19201502
103 Sällström KO, Larson O, Hedén P, Eriksson G, Glas JE, Ringborg U. Treatment of keloids with surgical excision and postoperative X-ray radiation. Scand J Plast Reconstr Surg Hand Surg. 1989;23(3):211–5. doi:10.3109/02844318909075120 2617222
104 Shen J, Lian X, Sun Y, . Hypofractionated electron-beam radiation therapy for keloids: retrospective study of 568 cases with 834 lesions. J Radiat Res. Sep 2015;56(5):811–7. doi:10.1093/jrr/rrv031 26224888
105 Ship AG, Weiss PR, Mincer FR, Wolkstein W. Sternal keloids: successful treatment employing surgery and adjunctive radiation. Ann Plast Surg. Dec 1993;31(6):481–7.8297076
106 Son Y, Phillips EON, Price KM, . Treatment of keloids with a single dose of low-energy superficial X-ray radiation to prevent recurrence after surgical excision: An in vitro and in vivo study. J Am Acad Dermatol. Nov 2020;83(5):1304–1314. doi:10.1016/j.jaad.2020.06.023 32540415
107 Song C, Wu HG, Chang H, Kim IH, Ha SW. Adjuvant single-fraction radiotherapy is safe and effective for intractable keloids. J Radiat Res. Sep 2014;55(5):912–6. doi:10.1093/jrr/rru025 24801475
108 Song KX, Liu S, Zhang MZ, . Hyperbaric oxygen therapy improves the effect of keloid surgery and radiotherapy by reducing the recurrence rate. J Zhejiang Univ Sci B. Nov. 2018;19(11):853–862. doi:10.1631/jzus.B1800132 30387335
109 Song KX, Wang YB, Zhang MZ, Wang XJ. A parasternal intercostal perforator flap for esthetic reconstruction after complete chest keloid resection: A retrospective observational cohort study. J Cosmet Dermatol. Dec 2018;17(6):1205–1208. doi:10.1111/jocd.12782 30393934
110 Speranza G, Sultanem K, Muanza T. Descriptive study of patients receiving excision and radiotherapy for keloids. Int J Radiat Oncol Biol Phys. Aug 1 2008;71(5):1465–9. doi:10.1016/j.ijrobp.2007.12.015 18249504
111 Sruthi K, Chelakkot PG, Madhavan R, Nair RR, Dinesh M. Single-fraction radiation: A promising adjuvant therapy to prevent keloid recurrence. J Cancer Res Ther. Oct–Dec 2018;14(6):1251–1255. doi:10.4103/jcrt.JCRT_20_17 30488839
112 Stahl S, Barnea Y, Weiss J, . Treatment of earlobe keloids by extralesional excision combined with preoperative and postoperative “sandwich" radiotherapy. Plast Reconstr Surg. Jan 2010;125(1):135–141. doi:10.1097/PRS.0b013e3181c2a46e 20048606
113 Sun Q, Yu ET, Zhou Y, Tong S, Zhou KJ, Guo S. Individualized surgery combined with radiotherapy and triamcinolone acetonide injection for the treatment of auricular keloids. BMC Surg. May 22 2021;21(1):256. doi:10.1186/s12893-021-01253-9 34022880
114 Supe SS, Sharma AK, Deka A, Deka B. Can we use radiotherapy alone in the treatment of keloids? Journal of the European Academy of Dermatology and Venereology. 1995;5(2):150–152.
115 Supe SS, Supe SJ, Rao SM, Deka AC, Deka BC. Treatment of keloids by 90Sr-90Y beta-rays. Strahlenther Onkol. Jul 1991;167(7):397–402.1858015
116 Ting W, Chong Y, Xu J, Huang J, Yu N, Liu Z. Treatment of keloids using plasma skin regeneration combined with radiation therapy under the evaluation of patient and observer scar assessment scale. Clin Cosmet Investig Dermatol. 2021;14:981–989. doi:10.2147/ccid.S321348
117 Tresoldi MM, Ivaldi GB, Porcu P, . Immediate postoperative treatment of keloids with intraoperative radiation therapy technology: A pilot study. Plast Reconstr Surg Glob Open. Sep 2021;9(9):e3738. doi:10.1097/gox.0000000000003738 34548996
118 van de Kar AL, Kreulen M, van Zuijlen PPM, Oldenburger F. The results of surgical excision and adjuvant irradiation for therapy-resistant keloids: a prospective clinical outcome study. Plast Reconstr Surg. Jun 2007;119(7):2248–2254. doi:10.1097/01.prs.0000260751.20217.28 17519728
119 Veen RE, Kal HB. Postoperative high-dose-rate brachytherapy in the prevention of keloids. Int J Radiat Oncol Biol Phys. Nov 15 2007;69(4):1205–8. doi:10.1016/j.ijrobp.2007.04.032 17967309
120 Viani GA, Stefano EJ, Afonso SL, De Fendi LI. Postoperative strontium-90 brachytherapy in the prevention of keloids: results and prognostic factors. Int J Radiat Oncol Biol Phys. Apr 1 2009;73(5):1510–6. doi:10.1016/j.ijrobp.2008.07.065 19101094
121 Wagner W, Schopohl B, Böttcher HD, Schnepper E. [Results of scar keloid prevention using contact irradiation with strontium 90]. Rontgenpraxis. Jul 1989;42(7):248–52. Ergebnisse der Narbenkeloidprophylaxe durch Kontaktbestrahlung mit Strontium 90.2756447
122 Wagner W, Alfrink M, Micke O, Schäfer U, Schüller P, Willich N. Results of prophylactic irradiation in patients with resected keloids--a retrospective analysis. Acta Oncol. 2000;39(2):217–20. doi:10.1080/028418600430806 10859014
123 Wang J, Min P, Grassetti L, . Preliminary outcomes of Distal IMAP and SEAP Flaps for the treatment of unstable keloids subject to recurrent inflammation and infections in the lower sternal and upper abdominal areas. J Reconstr Microsurg. Nov 2015;31(9):621–30. doi:10.1055/s-0035-1556078 26177690
124 Wang LZ, Ding JP, Yang MY, Chen B. Forty-five cases of chest keloids treated with subcutaneous super-tension-reduction suture combined with postoperative electron-beam irradiation. Dermatol Surg. Dec 2014;40(12):1378–84. doi:10.1097/dss.0000000000000163 25357171
125 Wang QG, Li XM, Zhang M, . [Effect of two dose fractionations on postoperative radiotherapy of keloid: an analysis of 107 patients]. Beijing Da Xue Xue Bao Yi Xue Ban. Feb 18 2014;46(1):169–72.24535372
126 Wang Y, Ma J, Zhang Z, Shen H. Combined surgical excision and electron external beam radiation improves the treatment of keloids: A descriptive study. Dermatol Ther. Jul 2020;33(4):e13494. doi:10.1111/dth.13494 32363669
127 Wen P, Wang T, Zhou Y, Yu Y, Wu C. A retrospective study of hypofractionated radiotherapy for keloids in 100 cases. Sci Rep. Feb 11 2021;11(1):3598. doi:10.1038/s41598-021-83255-4 33574426
128 Wong CM, Zhang J, Gui L, Zhou ZS. Individualized therapy for keloid in aural region. Chinese Journal of Clinical Rehabilitation.
129 Wu H, Dong G, Hu J, . Contour first-retrospective study of an algorithmic approach of auricular keloids. J Cosmet Dermatol. Apr 2023;22(4):1304–1311. doi:10.1111/jocd.15554 36575885
130 Yamawaki S, Naitoh M, Ishiko T, Muneuchi G, Suzuki S. Keloids can be forced into remission with surgical excision and radiation, followed by adjuvant therapy. Ann Plast Surg. Oct 2011;67(4):402–6. doi:10.1097/SAP.0b013e31820d684d 21407049
131 Yan D, Zhao B, Yang H, Zhu B, Wang J. A combination of nonoperative treatment modalities used for treatment of keloids. Dermatol Ther. Jan–Feb 2014;27(1):48–51. doi:10.1111/dth.12044 24502312
132 Yang X, Shao Y, Yu W, . A novel radiotherapy approach for keloids with intrabeam. Biomed Res Int. 2019;2019:4693528. doi:10.1155/2019/4693528 31428636
133 Yokokawa T, Shirai T, Kawasaki T, Furui S. Postoperative irradiation of earlobe. Nippon Hoshasen Shuyo Gakkai-Shi. 2006;18(3):141–145.
134 Zeng A, Song K, Zhang M, . The “Sandwich Therapy": A microsurgical integrated approach for presternal keloid treatment. Ann Plast Surg. Sep 2017;79(3):280–285. doi:10.1097/sap.0000000000000975 28758907
135 Zhang W, Liu Z, Zhu L, . Combining micro-plasma radio-frequency with hypofractionated electron-beam radiation as a novel treatment of keloids: A case series. Medicine (Baltimore). Nov 2019;98(48):e18094. doi:10.1097/md.0000000000018094 31770227
136 Zhang YG, Cen Y, Liu XX, Yu R, Xu XW. Clinical improvement in the therapy of aural keloids. Chin Med J (Engl). Dec 5 2009;122(23):2865–8.20092792
137 Zhu Y, Zhang Q, Gong T, . Sports bras improve chest keloids but outcomes are dependent on breast size: A retrospective analysis. Front Oncol. 2022;12:871115. doi:10.3389/fonc.2022.871115 35880163
138 Zhuang By, Hu Fc, You Y, Zhang L. Observation of the clinical efficacy of isotope phosphorus-32 dressing combined with diprospan and mucopolysaccharide polysulphate cream in the treatment of keloids. Journal of Cosmetic Dermatology. 2022;21(12):7140–7146.36169608

### Osteoarthritis: 15 Exclusions

1 Álvarez B, Montero A, Alonso R, . Low-dose radiation therapy for hand osteoarthritis: shaking hands again? Clin Transl Oncol. Mar 2022;24(3):532–539. doi:10.1007/s12094-021-02710-w 34585316
2 Álvarez B, Montero Á, Aramburu F, . Radiotherapy for ostheoarticular degenerative disorders: When nothing else works. Osteoarthr Cartil Open. Jan–Feb 2020;1(3–4):100016. doi:10.1016/j.ocarto.2019.100016 36475001
3 Hautmann MG, Hipp M, Neumaier U, . Radiotherapy for osteoarthritis of the ankle and tarsal joints-analysis of 66 joints. Strahlenther Onkol. Jun 2020;196(6):569–575. doi:10.1007/s00066-019-01551-5 31784803
4 Hautmann MG, Rechner P, Neumaier U, . Radiotherapy for osteoarthritis-an analysis of 295 joints treated with a linear accelerator. Strahlenther Onkol. Aug 2020;196(8):715–724. doi:10.1007/s00066-019-01563-1 31873780
5 Hermann RM, Trillmann A, Becker JN, Kaltenborn A, Nitsche M, Ruettermann M. Prospective evaluation of low-dose external beam radiotherapy (LD-EBRT) for painful trapeziometacarpal osteoarthritis (Rhizarthrosis) on pain, function, and quality of life to calculate the required number of patients for a prospective randomized study. Med Sci (Basel). Oct 27 2021;9(4)doi:10.3390/medsci9040066
6 Kaltenborn A, Bulling E, Nitsche M, Carl UM, Hermann RM. The field size matters: low dose external beam radiotherapy for thumb carpometacarpal osteoarthritis : Importance of field size. Strahlenther Onkol. Aug 2016;192(8):582–8. Relevanz der Feldgröße in der Reizbestrahlung bei Rhizarthrose : Relevanz der Feldgröße. doi:10.1007/s00066-016-0995-7 27300369
7 Koc BB, Schotanus MGM, Borghans R, . Short-term pain reduction after low-dose radiotherapy in patients with severe osteoarthritis of the hip or knee joint: a cohort study and literature review. Eur J Orthop Surg Traumatol. May 2019;29(4):843–847. doi:10.1007/s00590-019-02377-8 30649618
8 Marigi EM, Johnson QJ, Dancy ME, . Shoulder arthroplasty after prior external beam radiation therapy: a matched cohort analysis. J Shoulder Elbow Surg. Mar 2023;32(3):e85–e93. doi:10.1016/j.jse.2022.08.014 36183898
9 Razumov AN, Purigа AO, Yurova OV. [The long-term results of the application of the combined rehabilitative treatment in the patients presenting with knee osteoarthrosis]. Vopr Kurortol Fizioter Lech Fiz Kult. Nov–Dec 2015;92(6):42–44. doi:10.17116/kurort2015642-44 26841528
10 Rogers S, Eberle B, Vogt DR, . Prospective evaluation of changes in pain levels, quality of life and functionality after low dose radiotherapy for epicondylitis, plantar fasciitis, and finger osteoarthritis. Front Med (Lausanne). 2020;7:195. doi:10.3389/fmed.2020.00195 32509794
11 Sell S, Jany R, Kremling E, Esenwein S, Gaissmaier C, Küsswetter W. [Prevention of heterotopic ossification following cementless hip replacement using 5 × 2 Gy fractionated irradiation. A prospective study]. Z Orthop Ihre Grenzgeb. Jul–Aug 1996;134(4):375–80. Prävention heterotoper Ossifikationen nach zementfreiem Hüftgelenksersatz durch fraktionierte Radiatio mit 5 × 2 Gy. Eine prospektive Studie. doi:10.1055/s-2008-1039778 8928569
12 Szentesi M, Nagy Z, Géher P, Papp I, Kampen WU. A prospective observational study on the long-term results of (90)Yttrium citrate radiosynoviorthesis of synovitis in osteoarthritis of the knee joint. Eur J Nucl Med Mol Imaging. Jul 2019;46(8):1633–1641. doi:10.1007/s00259-019-04350-3 31129693
13 Szentesi M, Nagy Z, Géher P, Papp I, Kampen WU. [Long-term (10 year) results of Yttrium-90 radiosynoviorthesis in inflammed knee osteoarthritis: A prospective observational study]. Orv Hetil. Oct 25 2020;161(43):1831–1839. Yttrium-90 radiosynoviorthesis hosszú távú (10 éves) eredményei inflammált térdarthrosisban: Prospektív obszervációs vizsgálat. doi:10.1556/650.2020.31728 33099513
14 Usman Z, Maharaj SS, Kaka B. Effects of combination therapy and infrared radiation on pain, physical function, and quality of life in subjects with knee osteoarthritis: A randomized controlled study. Hong Kong Physiother J. Dec 2019;39(2):133–142. doi:10.1142/s1013702519500124 31889764
15 Van den Ende CH, Minten MJ, Leseman-Hoogenboom MM, . Long-term efficacy of low-dose radiation therapy on symptoms in patients with knee and hand osteoarthritis: Follow-up results of two parallel randomised, sham-controlled trials. The Lancet Rheumatology. 2020;2(1):e42–e49.38258275

### Peyronies Disease: 4 Exclusions

1 Kammerer R. [Radiotherapy of induratio penis plastica]. Z Urol Nephrol. May 1988;81(5):323–8. Strahlentherapie der Induratio penis plastica (IPP).3407340
2 Koren H, Alth G, Schenk GM, Jindra RH. Induratio penis plastica: effectivity of low-dose radiotherapy at different clinical stages. Urol Res. 1996;24(4):245–8. doi:10.1007/bf00295900 8873384
3 Rodrigues CI, Njo KH, Karim AB. Results of radiotherapy and vitamin E in the treatment of Peyronie’s disease. Int J Radiat Oncol Biol Phys. Feb 1 1995;31(3):571–6. doi:10.1016/0360-3016(94)00378-x 7852122
4 Weisser GW, Schmidt B, Hübener KH, Ahlemann LM, Kordonias D. [Radiation treatment of plastic induration of the penis]. Strahlenther Onkol. Jan 1987;163(1):23–8. Die Strahlenbehandlung der Induratio penis plastica.3544290

### Plantar Fasciitis: 11 Exclusions

1 Abdelmaqsoud A, Vorotniak N, Strauß D, Hentschel B. The analgesic effect of low-dose radiotherapy in treating benign musculoskeletal painful disorders using different energies: A retrospective cohort study. Journal of Radiotherapy in Practice. 2023;22:e78.
2 Badakhshi H, Buadch V. Low dose radiotherapy for plantar fasciitis. Treatment outcome of 171 patients. Foot (Edinb). Dec 2014;24(4):172–5. doi:10.1016/j.foot.2014.07.005 25201122
3 Hajtmanová E, Kinclová I, Kostková L, Hajtman A, Péc M. [Low-dose radiotherapy in the treatment of plantar fasciitis]. Klin Onkol. 2010;23(2):104–10. Nizkodávková rádioterapia v liecbe plantárnej fasciitídy.20465089
4 Heyd R, Tselis N, Ackermann H, Röddiger SJ, Zamboglou N. Radiation therapy for painful heel spurs: results of a prospective randomized study. Strahlenther Onkol. Jan 2007;183(1):3–9. doi:10.1007/s00066-007-1589-1
5 Kędzierawski P, Stando R, Macek P. Retrospective evaluation of the effectiveness of radiotherapy in patients with plantar fascitis (heel spurs). Rep Pract Oncol Radiother. May–Jun 2017;22(3):209–211. doi:10.1016/j.rpor.2016.11.001 28461784
6 Micke O, Seegenschmiedt MH. [Radiotherapy for painfull heel spurs]. MMW Fortschr Med. Apr 17 2008;150(16):32–4. Bestrahlung gegen den schmerzhaften Fersensporn.
7 Niewald M, Holtmann H, Prokein B, . Randomized multicenter follow-up trial on the effect of radiotherapy on painful heel spur (plantar fasciitis) comparing two fractionation schedules with uniform total dose: first results after three months’ follow-up. Radiat Oncol. Aug 19 2015;10:174. doi:10.1186/s13014-015-0471-z 26281833
8 Niewald M, Seegenschmiedt MH, Micke O, . Randomized, multicenter trial on the effect of radiation therapy on plantar fasciitis (painful heel spur) comparing a standard dose with a very low dose: mature results after 12 months’ follow-up. Int J Radiat Oncol Biol Phys. Nov 15 2012;84(4):e455–62. doi:10.1016/j.ijrobp.2012.06.022 22836057
9 Rogers S, Eberle B, Vogt DR, . Prospective evaluation of changes in pain levels, quality of life and functionality after low dose radiotherapy for epicondylitis, plantar fasciitis, and finger osteoarthritis. Front Med (Lausanne). 2020;7:195. doi:10.3389/fmed.2020.00195 32509794
10 Schäfer U, Micke O, Glashörster M, Rübe C, Prott FJ, Willich N. [The radiotherapy treatment of painful calcaneal spurs]. Strahlenther Onkol. Apr 1995;171(4):202–6. Strahlentherapeutische Behandlung des schmerzhaften Fersenbeinsporns.7740407
11 Surenkok S, Dirican B, Beyzadeoglu M, Oysul K. Heel spur radiotherapy and radiation carcinogenesis risk estimation. Radiat Med. Oct 2006;24(8):573–6. doi:10.1007/s11604-006-0075-5 17041794

### Pterygium: 31 Exclusions

1 Al-Salem KM, Saif AT, Saif PS. Comparing adjuvant beta radiation, mitomycin C, and conjunctival autograft in primary pterygium treatment, a three-year follow-up study. The Open Ophthalmology Journal. 2020;14(1)
2 Amano S, Motoyama Y, Oshika T, Eguchi S, Eguchi K. Comparative study of intraoperative mitomycin C and beta irradiation in pterygium surgery. Br J Ophthalmol. Jun 2000;84(6):618–21. doi:10.1136/bjo.84.6.618 10837388
3 Aswad MI, Baum J. Optimal time for postoperative irradiation of pterygia. Ophthalmology. Nov 1987;94(11):1450–1. doi:10.1016/s0161-6420(87)33267-1 3684219
4 Chayakul V. Postoperative mitomycin-C eye drop and beta radiation in the treatment of pterygia. J Med Assoc Thai. Sep 1991;74(9):373–6.1791389
5 Dash RG, Boparai MS. Pterygium--evaluation of management (primary & recurrent). Indian J Ophthalmol. Jan–Feb 1986;34(1):7–10.3127342
6 de Keizer RJ, Swart-van den Berg M, Baartse WJ. Results of pterygium excision with Sr 90 irradiation, lamellar keratoplasty and conjunctival flaps. Doc Ophthalmol. Sep–Oct 1987;67(1–2):33–44. doi:10.1007/bf00142695 3322749
7 Dusenbery KE, Alul IH, Holland EJ, Khan FM, Levitt SH. Beta irradiation of recurrent ptergia: results and complications. Int J Radiat Oncol Biol Phys. 1992;24(2):315–20. doi:10.1016/0360-3016(92)90687-d 1526870
8 Fukushima S, Inoue T, Inoue T, Ozeki S. Postoperative irradiation of pterygium with 90Sr eye applicator. Int J Radiat Oncol Biol Phys. Feb 1 1999;43(3):597–600. doi:10.1016/s0360-3016(98)00431-3 10078644
9 Gulani A, Dastur YK. Simultaneous pterygium and cataract surgery. J Postgrad Med. Jan–Mar 1995;41(1):8–11.10740692
10 Karabatsas CH, Marsh GW, Cook AM, Cook SD. Different therapeutic approaches and outcome in the treatment of pterygium. Eur J Ophthalmol. Jul–Sep 1998;8(3):148–52. doi:10.1177/112067219800800305 9793767
11 Lanchy P, Reguigui A, Urbajtel M, Hart M. [Beta therapy (strontium 90) associated with the removal of pterygium in order to avoid its recurrence]. Bull Soc Ophtalmol Fr. Jan 1989;89(1):153–5. La bétathérapie (Strontium 90) associée à l’exérèse du pterygion dans le but d’éviter sa récidive.2598368
12 Monteiro-Grillo I, Gaspar L, Monteiro-Grillo M, Pires F, Ribeiro da Silva JM. Postoperative irradiation of primary or recurrent pterygium: results and sequelae. Int J Radiat Oncol Biol Phys. Oct 1 2000;48(3):865–9. doi:10.1016/s0360-3016(00)00701-x 11020585
13 Nakamatsu K, Nishimura Y, Kanamori S, . Randomized clinical trial of postoperative strontium-90 radiation therapy for pterygia: treatment using 30 Gy/3 fractions vs. 40 Gy/4 fractions. Strahlenther Onkol. Jul 2011;187(7):401–5. doi:10.1007/s00066-011-2212-z 21713395
14 Nishimura Y, Nakai A, Yoshimasu T, . Long-term results of fractionated strontium-90 radiation therapy for pterygia. Int J Radiat Oncol Biol Phys. Jan 1 2000;46(1):137–41. doi:10.1016/s0360-3016(99)00419-8 10656385
15 Ozarda AT. Evaluation of postexcisional strontium 90 beta ray therapy for pterygium. South Med J. Nov 1977;70(11):1304. doi:10.1097/00007611-197711000-00017 918698
16 Pajic B, Greiner RH. Long term results of non-surgical, exclusive strontium-/yttrium-90 beta-irradiation of pterygia. Radiother Oncol. Jan 2005;74(1):25–9. doi:10.1016/j.radonc.2004.08.022 15683665
17 Pajic B, Pallas A, Aebersold D, Gruber G, Greiner RH. Prospective study on exclusive, nonsurgical strontium-/yttrium-90 irradiation of pterygia. Strahlenther Onkol. Aug 2004;180(8):510–6. doi:10.1007/s00066-004-1230-5 15292972
18 Pajic B, Pugnale-Verillotte N, Greiner RH, Pajic D, Eggspühler A. [Results of strontium-yttrium-90 for pterygia]. J Fr Ophtalmol. May 2002;25(5):473–9. Résultat de la thérapie au strontium-yttrium-90 des ptérygions.12048510
19 Pajonk F, Flick H, Mittelviefhaus H, Slanina J. Postoperative pterygium prevention by radiotherapy with strontium-90 beta-rays. Front Radiat Ther Oncol. 1997;30:259–64. doi:10.1159/000425712 9205909
20 Paryani SB, Scott WP, Wells JW, Jr., . Management of pterygium with surgery and radiation therapy. The North Florida Pterygium Study Group. Int J Radiat Oncol Biol Phys. Jan 1 1994;28(1):101–3. doi:10.1016/0360-3016(94)90146-5 8270429
21 Qin XJ, Chen HM, Guo L, Guo YY. Low-dose strontium-90 irradiation is effective in preventing the recurrence of pterygia: a ten-year study. PLoS One. 2012;7(8):e43500. doi:10.1371/journal.pone.0043500 22952695
22 Rigendinger F, Aebersold DM, Cvejic Z, Pajic B. Changes of corneal biomechanical properties upon exclusive Ytt-/Sr-90 irradiation of pterygium. Sensors (Basel). Feb 2 2021;21(3)doi:10.3390/s21030975
23 Schultze J, Hinrichs M, Kimmig B. The role of strontium-90 surface application in the prevention of recurrent pterygium. Strahlentherapie und Onkologie. 1996;172(8):417–421.8765343
24 Schultze J, Hinrichs M, Kimmig B. Results of adjuvant radiation therapy after surgical excision of pterygium. Ger J Ophthalmol. Jul 1996;5(4):207–10.8854104
25 Tarr KH, Constable IJ. Late complications of pterygium treatment. Br J Ophthalmol. Jul 1980;64(7):496–505. doi:10.1136/bjo.64.7.496 6968590
26 Vastardis I, Pajic B, Greiner RH, Pajic-Eggspuehler B, Aebersold DM. Prospective study of exclusive strontium-/yttrium-90 beta-irradiation of primary and recurrent pterygia with no prior surgical excision. Clinical outcome of long-term follow-up. Strahlenther Onkol. Dec 2009;185(12):808–14. doi:10.1007/s00066-009-2000-1 20013090
27 Viani GA, Stefano EJ, De Fendi LI, Fonseca EC. Long-term results and prognostic factors of fractionated strontium-90 eye applicator for pterygium. Int J Radiat Oncol Biol Phys. Nov 15 2008;72(4):1174–9. doi:10.1016/j.ijrobp.2008.02.075 18632216
28 Viani GA, De Fendi LI, Fonseca EC, Stefano EJ. Low or high fractionation dose β-radiotherapy for pterygium? A randomized clinical trial. Int J Radiat Oncol Biol Phys. Feb 1 2012;82(2):e181–5. doi:10.1016/j.ijrobp.2010.11.017 21596485
29 Yamada T, Mochizuki H, Ue T, Kiuchi Y, Takahashi Y, Oinaka M. Comparative study of different β-radiation doses for preventing pterygium recurrence. Int J Radiat Oncol Biol Phys. Dec 1 2011;81(5):1394–8. doi:10.1016/j.ijrobp.2010.07.1983 20889266
30 Yamamoto M, Hada Y, Akagi Y. Postoperative radiotherapy of pterygium with Strontium-90 plaque. The Journal of JASTRO. 2000;12(2):125–130.
31 Zhu X, Yu L. Care of patients with pterygium during postoperative 90Sr beta-ray therapy. Zhonghua hu li za zhi= Chinese Journal of Nursing. 1996;31(11):649–650.9304925