# APPENDIX A SEARCH STRATEGIES

## MEDLINE

((Keloid[MeSH Terms] OR “Pterygium”[Mesh] OR Pterygium* OR Keloid OR “Hidradenitis Suppurativa”[MeSH Terms] OR Suppurativ* Hidradenit* OR Acne Inversa* OR “Dupuytren Contracture”[MeSH Terms] OR (Dupuytren* AND (Disease* OR contracture)) OR Palmar Fibromatosis OR Ledderhos* Disease OR “Fibromatosis, Plantar”[Mesh] OR Plantar Fibromatosis OR “Penile Induration”[MeSH Terms] OR (Peni* AND (Fibromatosis OR Induration)) OR Fibrous Caverniti* OR Peyronie* Disease OR “Fasciitis, Plantar”[Mesh] OR Plantar Fasciitis OR Policeman* Heel OR Heel Spur Syndrome OR “Ossification, Heterotopic”[Mesh] OR heterotopic ossification)) AND ((Radiotherapy[MeSH Terms] OR Radiation[MeSH Terms] OR Targeted Radio* OR Radiatio* Therap* OR Radiatio* Treatment* OR radiotherap* OR electron beam))) NOT ((“address”[pt] OR “autobiography”[pt] OR “bibliography”[pt] OR “biography”[pt] OR “case reports”[pt] OR “comment”[pt] OR “congress”[pt] OR “dictionary”[pt] OR “directory”[pt] OR “festschrift”[pt] OR “government publication”[pt] OR “historical article”[pt] OR “interview”[pt] OR “lecture”[pt] OR “legal case”[pt] OR “legislation”[pt] OR “news”[pt] OR “newspaper article”[pt] OR “patient education handout”[pt] OR “periodical index”[pt] OR “comment”[ti] OR “Editorial" [Publication Type] OR “ephemera”[pt] OR “in vitro techniques”[mh] OR “introductory journal article”[pt] OR ((“Animals”[Mesh] OR rats[tw] OR rat[tw] OR cow[tw] OR cows[tw] OR chicken*[tw] OR horse[tw] OR horses[tw] OR mice[tw] OR mouse[tw] OR bovine[tw] OR sheep[tw] OR ovine[tw] OR murinae[tw] OR cats[tw] OR cat[tw] OR dog[tw] OR dogs[tw] OR rodent[tw]) NOT “Humans”[Mesh]))

## Search Strategy for Osteoarthritis

((((Osteoarthritis[MeSH Terms] OR Osteoarthrit* OR Osteoarthros* OR Degenerative Arthriti* OR Arthros*)) AND ((Radiotherapy[MeSH Terms] OR Radiation[MeSH Terms] OR Targeted Radio* OR Radiatio* Therap* OR Radiatio* Treatment* OR radiotherap* OR electron beam))) NOT ((“address”[pt] OR “autobiography”[pt] OR “bibliography”[pt] OR “biography”[pt] OR “case reports”[pt] OR “comment”[pt] OR “congress”[pt] OR “dictionary”[pt] OR “directory”[pt] OR “festschrift”[pt] OR “government publication”[pt] OR “historical article”[pt] OR “interview”[pt] OR “lecture”[pt] OR “legal case”[pt] OR “legislation”[pt] OR “news”[pt] OR “newspaper article”[pt] OR “patient education handout”[pt] OR “periodical index”[pt] OR “comment”[ti] OR “Editorial" [Publication Type] OR “ephemera”[pt] OR “in vitro techniques”[mh] OR “introductory journal article”[pt] OR ((“Animals”[Mesh] OR rats[tw] OR rat[tw] OR cow[tw] OR cows[tw] OR chicken*[tw] OR horse[tw] OR horses[tw] OR mice[tw] OR mouse[tw] OR bovine[tw] OR sheep[tw] OR ovine[tw] OR murinae[tw] OR cats[tw] OR cat[tw] OR dog[tw] OR dogs[tw] OR rodent[tw]) NOT “Humans”[Mesh]))) AND ((“2015/04/19”[Date - Publication] : “3000”[Date - Publication]))

## EMBASE

No. | Query | Results
#34 | #25 AND #32 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [18-04-2015]/sd NOT [02-04-2023]/sd | 911
#33 | #25 AND #32 | 1,941
#32 | #28 AND #29 OR #30 OR 31 | 257,976
#31 | arthros* | 84,930
#30 | Degenerative AND arthriti* | 8,691
#29 | osteoarthros* | 4,804
#28 | ‘osteoarthritis’ | 184,633
#27 | #18 AND #25 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim | 1,803
#26 | #18 AND #25 | 3,491
#25 | #19 OR #20 OR #21 OR #22 OR #23 OR #24 | 1,643,322
#24 | ‘electron beam’ | 17,384
#23 | radiatio* AND therap* | 506,879
#22 | radiatio* AND treatment* | 457,873
#21 | targeted AND radio* | 71,082
#20 | ‘radiation’ | 1,244,297
#19 | ‘radiotherapy’ | 738,219
#18 | #1 OR #2 OR #3 OR #4 OR #5 OR #6 OR #7 OR #8 OR #9 OR #10 OR #11 OR #12 OR #13 OR #14 OR #15 OR #16 OR #17 | 46,860
#17 | ‘heterotopic ossification’ | 10,560
#16 | heel AND spur AND syndrome | 120
#15 | ‘policeman heel’ | 42
#14 | ‘plantar fasciitis’ | 2,780
#13 | ‘peyronie disease’ | 4,914
#12 | fibrous AND ‘cavernitis’ | 1
#11 | penile AND fibromatosis | 35
#10 | penile AND induration | 444
#9 | ‘plantar fibromatosis’ | 309
#8 | ledderhose AND disease | 179
#7 | palmar AND fibromatosis | 191
#6 | dupuytren AND disease | 5,227
#5 | ‘dupuytren contracture’ | 4,088
#4 | acne AND inversa | 728
#3 | hidradenitis AND suppurativa OR ‘suppurative hidradenitis’ | 7,325
#2 | ‘pterygium’ | 5,770
#1 | ‘keloid’/exp OR ‘keloid’ | 8,590

## CLINICALTRIALS.GOV

Condition: (Keloid OR Pterygium OR Suppurativ* Hidradenit* OR Acne Inversa* OR Dupuytren* OR Palmar Fibromatosis OR Ledderhos* Disease OR Plantar Fibromatosis OR (Peni* AND (Fibromatosis OR Induration)) OR Fibrous Caverniti* OR Peyronie* Disease OR Plantar Fasc*) AND

Other terms: (radiation or radiotherapy)