# ABBREVIATIONS TABLE

Abbreviation: Definition
5-FU: 5-fluorouracil
AOFAS: American Orthopedic Foot and Ankle Score
AUSCAN: Australian/Canadian Hand Osteoarthritis Index
CI: Confidence interval
ESP: Evidence Synthesis Program
ESWT: Extracorporeal shock wave therapy
GRADE: Grading of Recommendations Assessment, Development and Evaluation
Gy: Gray
KQ: Key question
MD: Mean differences
MeSH: Medical Subject Headings
NMD: Net mean differences
NRCS: Nonrandomized comparative study
NRS: Numeric rating scale
NS: Not significant
NSAIDs: Non-steroidal anti-inflammatory drugs
OR: Odds ratios
OSAS: Observer Scar Assessment Scale
POSAS: Patient and Observer Scar Assessment Scale
PRP: Rich plasma therapy
PSAS: Patient Scar Assessment Scale
RCT: Randomized controlled trial
RD: Risk differences
REML: Restricted maximum-likelihood estimation
ROBINS-I: Risk Of Bias In Non-randomized Studies – of Interventions
RT: Radiation treatment
SF-SACRAH: Short Form Score for the Assessment and Quantification of Chronic Rheumatic affections of the hands
SF12: 12 item Short Forms
SF36: Short Form Health Survey
SRDR+: Systematic Review Data Repository-Plus
TEP: Technical Expert Panel
VA: Veterans Affairs
VA-NROP: VA National Radiation Oncology Program
VAS: Visual analog scale
VHA: Veterans Health Administration
VSS: Vancouver Scar Scale
WOMAC: Western Ontario and McMaster University Osteoarthritis Index Scale