# REFERENCES

1 Matula SR, Trivedi AN, Miake-Lye I, Glassman PA, Shekelle P, Asch S. Comparisons of quality of surgical care between the US Department of Veterans Affairs and the private sector. J Am Coll Surg. Dec 2010;211(6):823–32. doi:10.1016/j.jamcollsurg.2010.09.001 21109159
2 O’Hanlon C, Huang C, Sloss E, Comparing VA and Non-VA Quality of Care: A Systematic Review. J Gen Intern Med. Jan 2017;32(1):105–121. doi:10.1007/s11606-016-3775-2 27422615
3 Baker A. Crossing the Quality Chasm: A New Health System for the 21st Century. vol 323(7322). BMJ; 2011.
4 Veterans Access, Choice, and Accountability Act of 2014, (2014).
5 VA MISSON Act of 2018, (2018).
6 Institute of Medicine. Crossing the Quality Chasm: A New Health System for the 21st Century. Institute of Medicine; 2001.
7 Jones LG, Sin MK, Hage FG, Characteristics and outcomes of patients with advanced chronic systolic heart failure receiving care at the Veterans Affairs versus other hospitals: insights from the Beta-blocker Evaluation of Survival Trial (BEST). Circ Heart Fail. Jan 2015;8(1):17–24. doi:10.1161/circheartfailure.114.001300 25480782
8 Florez HJ, Ghosh A, Pop-Busui R, Differences in complications, cardiovascular risk factor, and diabetes management among participants enrolled at veterans affairs (VA) and non-VA medical centers in the glycemia reduction approaches in diabetes: A comparative effectiveness study (GRADE). Diabetes Res Clin Pract. Dec 28 2021;184:109188. doi:10.1016/j.diabres.2021.109188 34971663
9 Augustine JJ, Arrigain S, Balabhadrapatruni K, Desai N, Schold JD. Significantly Lower Rates of Kidney Transplantation among Candidates Listed with the Veterans Administration: A National and Local Comparison. J Am Soc Nephrol. Oct 2018;29(10):2574–2582. doi:10.1681/asn.2017111204 30006419
10 Burke JF, Kerr EA, McCammon RJ, Holleman R, Langa KM, Callaghan BC. Neuroimaging overuse is more common in Medicare compared with the VA. Neurology. Aug 23 2016;87(8):792–8. doi:10.1212/wnl.0000000000002963 27402889
11 Lee D, Begley CE. Delays in Seeking Health Care: Comparison of Veterans and the General Population. J Public Health Manag Pract. Mar/Apr 2017;23(2):160–168. doi:10.1097/phh.0000000000000420 27115981
12 Fortney JC, Carey EP, Rajan S, Rise PJ, Gunzburger EC, Felker BL. A comparison of patient-reported mental health outcomes for the Department of Veterans Affairs’ regional telehealth and Community Care Programs. Health Serv Res. Aug 2022;57(4):755–763. doi:10.1111/1475-6773.13993 35467011
13 Petros V, Tsambikos E, Madhoun M, Tierney WM. Impact of Community Referral on Colonoscopy Quality Metrics in a Veterans Affairs Medical Center. Clin Transl Gastroenterol. Jan 1 2022;13(3):e00460. doi:10.14309/ctg.0000000000000460 35081542
14 Heidenreich PA, Zapata A, Shieh L, Oliva N, Sahay A. Patient ratings of Veterans Affairs and affiliated hospitals. Am J Manag Care. Jun 2017;23(6):382–384.28817300
15 Mody L, Greene MT, Saint S, Comparing Catheter-Associated Urinary Tract Infection Prevention Programs Between Veterans Affairs Nursing Homes and Non-Veterans Affairs Nursing Homes. Infect Control Hosp Epidemiol. Mar 2017;38(3):287–293. doi:10.1017/ice.2016.279 27917728
16 Axon RN, Gebregziabher M, Everett CJ, Heidenreich P, Hunt KJ. Dual health care system use is associated with higher rates of hospitalization and hospital readmission among veterans with heart failure. Am Heart J. Apr 2016;174:157–63. doi:10.1016/j.ahj.2015.09.023 26995383
17 Shields MC, Rosenthal MB. Quality of Inpatient Psychiatric Care at VA, Other Government, Nonprofit, and For-Profit Hospitals: A Comparison. Psychiatr Serv. Mar 1 2017;68(3):225–230. doi:10.1176/appi.ps.201600074 27745537
18 Presley CJ, Kaur K, Han L, Aggressive End-of-Life Care in the Veterans Health Administration versus Fee-for-Service Medicare among Patients with Advanced Lung Cancer. J Palliat Med. Jun 2022;25(6):932–939. doi:10.1089/jpm.2021.0436 35363053
19 Barnett PG, Hong JS, Carey E, Grunwald GK, Joynt Maddox K, Maddox TM. Comparison of Accessibility, Cost, and Quality of Elective Coronary Revascularization Between Veterans Affairs and Community Care Hospitals. JAMA Cardiol. Feb 1 2018;3(2):133–141. doi:10.1001/jamacardio.2017.4843 29299607
20 Nuti SV, Qin L, Rumsfeld JS, Association of Admission to Veterans Affairs Hospitals vs Non-Veterans Affairs Hospitals With Mortality and Readmission Rates Among Older Men Hospitalized With Acute Myocardial Infarction, Heart Failure, or Pneumonia. JAMA. Feb 9 2016;315(6):582–92. doi:10.1001/jama.2016.0278 26864412
21 Thorpe CT, Gellad WF, Mor MK, Effect of Dual Use of Veterans Affairs and Medicare Part D Drug Benefits on Antihypertensive Medication Supply in a National Cohort of Veterans with Dementia. Health Serv Res. Dec 2018;53 Suppl 3(Suppl Suppl 3):5375–5401. doi:10.1111/1475-6773.13055
22 Intrator O, O’Hanlon CE, Makineni R, Scott WJ, Saliba D. Comparing Post-Acute Populations and Care in Veterans Affairs and Community Nursing Homes. J Am Med Dir Assoc. Dec 2021;22(12):2425–2431.e7. doi:10.1016/j.jamda.2021.10.007 34740562
23 Jia H, Pei Q, Sullivan CT, Poststroke Rehabilitation and Restorative Care Utilization: A Comparison Between VA Community Living Centers and VA-contracted Community Nursing Homes. Med Care. Mar 2016;54(3):235–42. doi:10.1097/mlr.0000000000000494 26807537
24 Wang V, Coffman CJ, Stechuchak KM, Survival among Veterans Obtaining Dialysis in VA and Non-VA Settings. J Am Soc Nephrol. Jan 2019;30(1):159–168. doi:10.1681/asn.2018050521 30530657
25 Wang V, Coffman CJ, Stechuchak KM, Comparative Assessment of Utilization and Hospital Outcomes of Veterans Receiving VA and Non-VA Outpatient Dialysis. Health Serv Res. Dec 2018;53 Suppl 3(Suppl Suppl 3):5309–5330. doi:10.1111/1475-6773.13022
26 Kurella Tamura M, Thomas IC, Montez-Rath ME, Dialysis Initiation and Mortality Among Older Veterans With Kidney Failure Treated in Medicare vs the Department of Veterans Affairs. JAMA Intern Med. May 1 2018;178(5):657–664. doi:10.1001/jamainternmed.2018.0411 29630695
27 Cashion W, Gellad WF, Sileanu FE, Source of Post-Transplant Care and Mortality among Kidney Transplant Recipients Dually Enrolled in VA and Medicare. Clin J Am Soc Nephrol. Mar 8 2021;16(3):437–445. doi:10.2215/CJN.10020620 33602753
28 Blay E Jr., DeLancey JO, Hewitt DB, Chung JW, Bilimoria KY. Initial Public Reporting of Quality at Veterans Affairs vs Non-Veterans Affairs Hospitals. JAMA Intern Med. Jun 1 2017;177(6):882–885. doi:10.1001/jamainternmed.2017.0605 28418527
29 Anhang Price R, Sloss EM, Cefalu M, Farmer CM, Hussey PS. Comparing Quality of Care in Veterans Affairs and Non-Veterans Affairs Settings. J Gen Intern Med. Oct 2018;33(10):1631–1638. doi:10.1007/s11606-018-4433-7 29696561
30 LaBedz SL, Krishnan JA, Chung YC, Chronic Obstructive Pulmonary Disease Outcomes at Veterans Affairs Versus Non-Veterans Affairs Hospitals. Chronic Obstr Pulm Dis. Jul 28 2021;8(3):306–313. doi:10.15326/jcopdf.2021.0201 33975417
31 Vercammen-Grandjean C, Schopfer DW, Zhang N, Whooley MA. Participation in Pulmonary Rehabilitation by Veterans Health Administration and Medicare Beneficiaries After Hospitalization for Chronic Obstructive Pulmonary Disease. J Cardiopulm Rehabil Prev. Nov 2018;38(6):406–410. doi:10.1097/hcr.0000000000000357 30252780
32 Watkins KE, Smith B, Akincigil A, The Quality of Medication Treatment for Mental Disorders in the Department of Veterans Affairs and in Private-Sector Plans. Psychiatr Serv. Apr 1 2016;67(4):391–6. doi:10.1176/appi.ps.201400537 26567931
33 McCulloch K, Pastorek NJ, Miller BI, Clinician versus Veteran ratings on the Mayo-Portland Participation Index in veterans with a history of mild traumatic brain injury. J Head Trauma Rehabil. Jan-Feb 2015;30(1):38–46. doi:10.1097/htr.0000000000000041 24695266
34 Gidwani-Marszowski R, Faricy-Anderson K, Asch SM, Illarmo S, Ananth L, Patel MI. Potentially avoidable hospitalizations after chemotherapy: Differences across medicare and the Veterans Health Administration. Cancer. Jul 15 2020;126(14):3297–3302. doi:10.1002/cncr.32896 32401340
35 Scheuner MT, Huynh AK, Chanfreau-Coffinier C, Demographic Differences Among US Department of Veterans Affairs Patients Referred for Genetic Consultation to a Centralized VA Telehealth Program, VA Medical Centers, or the Community. JAMA Netw Open. Apr 1 2022;5(4):e226687. doi:10.1001/jamanetworkopen.2022.6687 35404460
36 Penn M, Bhatnagar S, Kuy S, Comparison of Wait Times for New Patients Between the Private Sector and United States Department of Veterans Affairs Medical Centers. JAMA Netw Open. Jan 4 2019;2(1):e187096. doi:10.1001/jamanetworkopen.2018.7096 30657532
37 Gurewich D, Shwartz M, Beilstein-Wedel E, Davila H, Rosen AK. Did Access to Care Improve Since Passage of the Veterans Choice Act?: Differences Between Rural and Urban Veterans. Med Care. Jun 1 2021;59(Suppl 3):S270–S278. doi:10.1097/MLR.0000000000001490 33976076
38 Griffith KN, Ndugga NJ, Pizer SD. Appointment Wait Times for Specialty Care in Veterans Health Administration Facilities vs Community Medical Centers. JAMA Netw Open. Aug 3 2020;3(8):e2014313. doi:10.1001/jamanetworkopen.2020.14313 32845325
39 Feyman Y, Asfaw DA, Griffith KN. Geographic Variation in Appointment Wait Times for US Military Veterans. JAMA Netw Open. Aug 1 2022;5(8):e2228783. doi:10.1001/jamanetworkopen.2022.28783 36006640
40 Vanneman ME, Wagner TH, Shwartz M, Veterans’ Experiences With Outpatient Care: Comparing The Veterans Affairs System With Community-Based Care. Health Aff (Millwood). Aug 2020;39(8):1368–1376. doi:10.1377/hlthaff.2019.01375 32744943
41 Davila H, Rosen AK, Beilstein-Wedel E, Shwartz M, Chatelain L Jr., Gurewich D. Rural Veterans’ Experiences With Outpatient Care in the Veterans Health Administration Versus Community Care. Med Care. Jun 1 2021;59(Suppl 3):S286–S291. doi:10.1097/MLR.0000000000001552 33976078
42 Makarov DV, Ciprut S, Walter D, Association Between Guideline-Discordant Prostate Cancer Imaging Rates and Health Care Service Among Veterans and Medicare Recipients. JAMA Netw Open. Aug 3 2018;1(4):e181172. doi:10.1001/jamanetworkopen.2018.1172 30646111
43 Gidwani R, Asch SM, Needleman J, End-of-Life Cost Trajectories in Cancer Patients Treated by Medicare versus the Veterans Health Administration. J Am Geriatr Soc. Apr 2021;69(4):916–923. doi:10.1111/jgs.16941 33368171
44 Pickering AN, Zhao X, Sileanu FE, Assessment of Care Cascades Following Low-Value Prostate-Specific Antigen Testing Among Veterans Dually Enrolled in the US Veterans Health Administration and Medicare Systems. JAMA Netw Open. Dec 1 2022;5(12):e2247180. doi:10.1001/jamanetworkopen.2022.47180 36520431
45 Eid MA, Barnes JA, Trooboff SW, Goodney PP, Wong SL. A Comparison of Surgical Quality and Patient Satisfaction Indicators Between VA Hospitals and Hospitals Near VA Hospitals. J Surg Res. Nov 2020;255:339–345. doi:10.1016/j.jss.2020.05.071 32599453
46 Billig JI, Evans RR, Kerr EA, Hayward RA, Sears ED. The Impact of Community Care Referral on Time to Surgery for Veterans With Carpal Tunnel Syndrome. Med Care. Jun 1 2021;59(Suppl 3):S279–S285. doi:10.1097/MLR.0000000000001469 33976077
47 Rosen A, Beilstein-Wedel EE, Harris AH, Comparing Postoperative Readmission Rates between Veterans Receiving Total Knee Arthroplasty in the Veterans Health Administration (VA) versus Community Care. Medical Care. 2021;
48 Frisch NB, Courtney PM, Darrith B, Copeland LA, Gerlinger TL. Veterans Undergoing Total Hip and Knee Arthroplasty: 30-day Outcomes as Compared to the General Population. J Am Acad Orthop Surg. Nov 15 2020;28(22):923–929. doi:10.5435/jaaos-d-19-00775 32004175
49 Regenbogen SE ON, Dimick JB. Hospital Characteristics and Participation in the National Surgical Quality Improvement Program. Journal of Surgical Research. 2012;172(2)
50 Hutt E, Radcliff TA, Henderson W, Maciejewski M, Cowper-Ripley D, Whitfield E. Comparing Survival Following Hip Fracture Repair in VHA and Non-VHA Facilities. Geriatr Orthop Surg Rehabil. Mar 2015;6(1):22–7. doi:10.1177/2151458514561787 26246949
51 Williams CD, Alpert N, Redding TSt, Racial Differences in Treatment and Survival among Veterans and Non-Veterans with Stage I NSCLC: An Evaluation of Veterans Affairs and SEER-Medicare Populations. Cancer Epidemiol Biomarkers Prev. Jan 2020;29(1):112–118. doi:10.1158/1055-9965.Epi-19-0245 31624076
52 Kesseli SJ, Samoylova ML, Moris D, Outcomes in Kidney Transplantation Between Veterans Affairs and Civilian Hospitals: Considerations in the Context of the MISSION Act. Ann Surg. Sep 1 2020;272(3):506–510. doi:10.1097/sla.0000000000004119 32773623
53 Mull HJ, Kabdiyeva A, Ndugga N, Gordon SH, Garrido MM, Pizer SD. What is the role of selection bias in quality comparisons between the Veterans Health Administration and community care? Example of elective hernia surgery. Health Serv Res. Dec 7 2022;doi:10.1111/1475-6773.14113
54 Wu AM, Wu CM, Tseng VL, Characteristics Associated With Receiving Cataract Surgery in the US Medicare and Veterans Health Administration Populations. JAMA Ophthalmol. Jul 1 2018;136(7):738–745. doi:10.1001/jamaophthalmol.2018.1361 29800973
55 Pettey WBP, Wagner TH, Rosen AK, Beilstein-Wedel E, Shwartz M, Vanneman ME. Comparing Driving Miles for Department of Veterans Affairs-delivered Versus Department of Veterans Affairs-purchased Cataract Surgery. Med Care. Jun 1 2021;59(Suppl 3):S307–S313. doi:10.1097/MLR.0000000000001491 33976081
56 Wagner TH, Lo J, Beilstein-Wedel E, Vanneman ME, Shwartz M, Rosen AK. Estimating the Cost of Surgical Care Purchased in the Community by the Veterans Health Administration. MDM Policy Pract. Jul-Dec 2021;6(2):23814683211057902. doi:10.1177/23814683211057902 34820527
57 Heiden BT, Eaton DB Jr., Chang SH, Comparison between Veteran and Non-Veteran Populations with Clinical Stage I Non-Small Cell Lung Cancer Undergoing Surgery. Ann Surg. May 11 2021;doi:10.1097/sla.0000000000004928
58 Chan DC, Danesh K, Costantini S, Card D, Taylor L, Studdert DM. Mortality among US veterans after emergency visits to Veterans Affairs and other hospitals: retrospective cohort study. BMJ. Feb 16 2022;376:e068099. doi:10.1136/bmj-2021-068099 35173019
59 George EL, Massarweh NN, Youk A, Comparing Veterans Affairs and Private Sector Perioperative Outcomes After Noncardiac Surgery. JAMA Surg. Dec 29 2021;doi:10.1001/jamasurg.2021.6488
60 Harris AHS, Beilstein-Wedel EE, Rosen AK, Comparing Complication Rates After Elective Total Knee Arthroplasty Delivered Or Purchased By The VA. Health Aff (Millwood). Aug 2021;40(8):1312–1320. doi:10.1377/hlthaff.2020.01679 34339235
61 Rosen AK, Vanneman ME, O’Brien WJ, Comparing cataract surgery complication rates in veterans receiving VA and community care. Health Serv Res. Oct 2020;55(5):690–700. doi:10.1111/1475-6773.13320 32715468