# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- David Atkins, MD, MPH
  Director of VA Health Services Research and Development
  Veterans Health Administration
- Gerard Cox, MD, MHA
  Assistant Under Secretary for Health for Quality and Patient Safety
  Veterans Health Administration
- Kristin Cunningham, PMP
  Executive Officer to the Deputy Under Secretary for Health for Community Care
  Veterans Health Administration
- Julianne Flynn, MD
  Acting Deputy to the Assistant Under Secretary for Health for Office of Community Care Performing the Delegable Duties to the Assistant Under Secretary for Health Office of Community Care
  Veterans Health Administration
  Chief of Staff, VA South Texas Health Care
- Joseph Francis, MD, MPH
  Executive Director for the Office of Analytics and Performance Integration in the Office of Quality and Patient Safety
  Veterans Health Administration

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix J for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.