# DISUSSION

Our systematic review identified 38 studies of non-surgical care and 198 studies of surgical care comparing quality, safety, access, patient experience, or efficiency/cost between VA-delivered care and non-VA-delivered care. The large majority of studies assessed quality and safety, followed by comparisons of access to care. Few studies—only 7 and 10, respectively—assessed patient experience or cost/efficiency. We found no studies comparing VA to non-VA care on equity.

In the domain of quality and safety, the great majority of studies found that VA care is as good as, or better than, care in the community. This was the case for both surgical care and non--surgical care, and for community care of Veterans and community care of non-Veterans. For the domains of access and of cost/efficiency, the studies were more evenly distributed between the categories of VA care is better, VA and community care are about the same, and community care is better. The few studies of patient experience found that VA care and community care were about the same or VA care was better. We did not identify any study the found that patient experience was better in community care.

The studies best able to address implications of the CHOICE and MISSION acts were designed to capture data of Veterans receiving VA-paid community care. In these comparisons, quality and safety was generally better in VA-delivered care for studies of nonsurgical care and of about equal or mixed results for studies of surgical care. Differences between sites of care were more mixed for the other domains: access, patient experience, and cost.

Key among the quality and safety outcomes is mortality. Among studies of surgical care, the overall trend of the broader domain held. One study of Veterans in community care had equivalent mortality after CABG, and 5 other studies comparing mortality to non-Veterans were distributed between lower mortality in the VA (after lung resection, non-cardiac surgery, and surgical inpatient deaths) or a mixture of VA better and no difference (2 studies of kidney transplant); there were no cases of lower mortality in community care among the high-quality studies.

The few exceptions to these general findings deserve noting. For surgical care, there was a consistent finding that VA length of stay was longer than in non-VA care. In 2 studies of procedures, the investigators found that in some cases VA-purchased care was less expensive than the estimate of costs for VA to deliver the procedure. In several studies of both non-surgical care and surgical care, there was a greater travel distance to receive care from VA than from the community, although the importance of these differences may vary for different Veteran stakeholders. Lastly, even in studies that found, on average, that VA care was better than community care, there was some regional variation such that in a few geographic areas VA care had worse outcomes than community care or that a few measures of quality were better in the community than at VA.

These results notwithstanding, the overarching conclusion from the published studies since 2015 reinforces the conclusions of the 2 prior reviews of studies comparing VA care to non-VA care: on average, VA care performs better than or similar to non-VA care in the domain of quality and safety. While this relationship persists nationally, studies comparing local VA facilities to their community counterpart may reveal areas of local deviance from national trends. Identifying where there are such differences in care will be critical to ongoing comparisons in the future. In addition, these findings highlight focused areas for potential VA performance improvement, such as hip fracture repair.

This review expands those earlier conclusions to include the outcome domains of access, patient experience, and efficiency/cost. For these domains, we found more studies in this review (studies published since 2015) than in the prior review that covered 2005–2015 (29 studies vs 19 studies). Thus, we believe we can draw some early conclusions about comparisons between VA and non-VA care: while not as striking as in the quality/safety domain, studies tended to find that VA care was about the same or better than non-VA care, with the exceptions of travel distance and length of stay.

How might these data be used? First, comparisons are useful in identifying possible quality issues where VA performance should be improved. Looking at specific outcomes is important. Second, comparisons of VA versus community care paid for by VA are critical to shaping decisions about the expansion of the program and determining whether sending Veterans out for care in an effort to improve timeliness or convenience comes at a cost in terms of clinical outcomes. Third, some comparisons are useful for judging the potential advantages of the VA’s national system of integrated care versus care delivery in less organized settings, such as delivery of preventive care and control of chronic disease.

## LIMITATIONS

In addition to the usual limitation of any systematic review, namely the quantity and quality of the original studies, we add the possibility of publication bias or subconscious investigator bias, in that most of the published studies are by VA authors. We scrutinized each study for objective evidence of bias and diminished the degree to which studies with such bias contributed to our overall conclusions. Nevertheless, we cannot assess the degree to which unmeasurable bias or the decision to undertake a comparative study and what topics to focus on are influenced by VA investigators. This may be something that can only be resolved with difficulty and waiting until other health systems adopt the same kind of learning health system culture that VA has, which results in self-inspection of quality of care compared to other health care systems.

Beyond this, the most important limitation to any of these comparisons is the possibility of confounding by choice of care delivery site—in other words, the comparability of the patients getting VA care to the patients getting care outside VA, whether they be Veterans getting community care or non-Veterans getting community care. Studies attempted to control for this by using multivariable methods to adjust for baseline differences between groups, but these methods are limited by the availability of baseline variables and the degree to which those variables are captured. Thus, 1 study of outcomes of heart failure care was able to adjust for the presence or absence of a large number of comorbidities, but not able to adjust for baseline differences in the severity of heart failure. Providers in fee-for-service health care have a financial incentive to code for comorbidities that VA providers do not have; thus, there may be differential capture of this between patients in VA and outside VA care. Likewise, most studies were not able to adjust for differences in the social determinants of health, which may affect everything from length of stay to readmission to outcomes of chronic illness. VA patients are known to bear a heavier burden of social determinants of health than patients outside VA care. To the extent these burdens are uncaptured and unadjusted for, this discrepancy places VA care at a disadvantage compared to patients outside VA care for such outcomes. The bias introduced by this heavier burden makes the findings that VA care was equivalent to or better than non-VA care even more exceptional.

An additional limitation in drawing overall conclusions is the relative value placed on different outcomes. For example, the small but statistically significant benefit of VA care in terms of mortality seen in several studies would seem to be more “important” than the small but statistically significant benefit seen for community care in post-discharge receipt of pulmonary rehabilitation for patients with COPD—in other words, one study doesn’t balance out the other. Similarly, the degree to which travel distance is an outcome of importance to Veterans is unknown; it was included as an outcome in this review since travel distance was a criterion of eligibility for care under the CHOICE act. But we did not attempt to classify the outcomes as “important” or “less important,” since at the edges this would invariably require subjective decisions by the research team—for example, which is more important, a shorter wait time for a urology appointment or a longer length of stay after joint replacement surgery?—and the value of these outcomes maybe different to different stakeholders. Thus, we presented the outcomes without attempting to classify them by degree of importance.

An additional limitation in arriving at overarching conclusions is that the conditions and procedures for which such comparisons have been published are only a small fraction of the care Veterans receive; their results cannot be generalized to all kinds of care.

## FUTURE RESEARCH

Despite several dozen publications comparing VA care with non-VA care, there are a number of clinical areas where there are large amounts of care delivered in the community through the MISSION act, such as physical medicine and rehabilitation, yet no studies comparing quality of care. In addition, studies that report lower cost for purchased community care for some procedures (joint replacement, CABG) than the estimates of cost for VA to deliver that care need to have more sophisticated analyses that model what would happen if VA increases the purchase of community care. It would greatly facilitate comparisons of VA care to non-VA care if non-VA care had the same degree of comprehensive performance data that are publicly available. Lastly, we expect that comparing VA care with non-VA care is a moving target, unlike, for example, the value of beta blockers after myocardial infarction, and thus this topic needs regular updating of published studies to keep this review up to date.

## CONCLUSIONS

In general, most published studies of comparisons of quality of care show that Veterans getting care from VA get the same or better quality care than Veterans getting community care or the general public getting non-VA care.