# METHODS

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 Compare and contrast studies that assess VA and non-VA quality of care for non-surgical medical conditions.
KQ2 Compare and contrast studies that assess VA and non-VA quality of care for surgical conditions.

We were tasked with categorizing included studies into 2 groups:

1. Veterans receiving care at VA compared with Veterans receiving care in the community, whether through CHOICE or the MISSION Act or on their own initiative
2. Veterans receiving care at VA compared with the general population/non-Veterans receiving care from non-VA providers.

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022314154).

## DATA SOURCES AND SEARCHES

We conducted broad searches using terms relating to Veterans health and community health services or private sector. To identify articles relevant to the key questions, a research librarian searched PubMed, APA PsycINFO, and Web of Science (1/1/2015–3/15/2023). The start date was chosen to match the end date of the most recent review by O’Hanlon.^2^ Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. See Appendix A for complete search strategy.

## STUDY SELECTION

Two sets of team members (1 team specializing in surgical titles and the other specializing in non-surgical titles) working independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by independent team members with any disagreements resolved through discussion. Studies were included at either the abstract or the full-text level if they were original research studies of any design and made comparisons about the quality of care provided in VA Medical Centers and outpatient clinics compared with care provided in other health systems, ie, the general population. We included as quality any outcomes within the Institute of Medicine 6 domains of health care: quality, safety, access, patient experience, efficiency (cost), and equity.^6^

### Eligibility Criteria

This review included studies that met the following criteria:

P opulation: | Patients receiving care from VA or non-VA providers, in the following categories: Veterans receiving care in VA compared to Veterans receiving care in the community, either VA-paid or not VA-paid; Veterans receiving care in VA compared to general population patients receiving care in the community
I ntervention: | N/A
C omparator: | Community care
O utcomes: | Quality in any of the Institute of Medicine domains: clinical quality, safety, efficiency, access, patient experience, equity
T iming: | 2015 present
S etting: | Veteran and non-VA US health care providers
S tudy Design: | Original research studies of any design, no randomized comparisons are expected, studies are expected to be cohort studies with or without matching

## DATA ABSTRACTION AND ASSESSMENT

The eligibility criteria are as follows. The population was patients receiving care from VA or non-VA providers; this included 2 possible comparisons, (1) Veterans receiving VA care versus Veterans receiving non-VA care (community care [CC]) or (2) Veterans receiving VA care versus the general population of non-Veteran patients receiving non-VA care in the community (non-VA). Outcomes included any of the Institute of Medicine aims of health care. We classified costs and length of stay as efficiency outcomes.

At the abstract stage, information on the medical or surgical condition, type of outcome reported, populations under comparison, and years of data were collected. Articles meeting inclusion criteria underwent a second screening and additional information was abstracted: whether study years were contemporaneous, sampling approach, geographic representativeness, similarity of outcomes between the comparison groups, sample size, years of data collected, control variables, outcomes, findings, and statistical methods. All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with an additional reviewer.

## RISK OF BIAS/QUALITY ASSESSMENT

The risk of bias for studies of this type centers around the representativeness of the samples being assessed and whether the measures of performance are valid and applied equally across both groups. For this review we adapted the 6 items originally used in the 2010 review to the following:

1) whether the time frames for the measurement are contemporaneous for both groups;
2) whether the samples are national or representative for both groups;
3) whether the quality measures used to assess care in both groups are identical or nearly identical;
4) whether the analysis had enough sample size and appropriate statistical methods to test the hypothesis.

Studies could fully meet a criterion, partially meet a criterion, or fail a criterion. Studies fully meeting all of these criteria were considered to be “good” quality and given greater weight than studies not meeting all of the criteria, which were considered to be “fair” quality. Studies failing 1 or more criteria were not included in the analysis.

## SYNTHESIS

Because of the heterogeneity in the comparison groups, outcome domains and procedure types/health conditions, pooling the data for a meta-analysis was not possible and a narrative synthesis was performed. Studies were first classified by 1 of 4 domains: quality and safety, access, patient experience, and cost. One study may report more than 1 domain. Within domains, studies were grouped by surgical discipline or by clinical condition (cardiovascular, mental health, etc). If multiple cost outcomes were reported, total cost was abstracted. Studies were grouped into 2 categories based on their quality assessment: those that had no obvious flaws limiting their internal or external validity, and those that had some flaws limiting internal or external validity. Studies with serious internal validity flaws were not included in the synthesis (see Appendix B).