# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the Office of the Assistant Under Secretary for Health for Quality and Patient Safety. Findings from this review will be used to inform internal and external stakeholders (VSOs, media, Congress, etc) about the quality of VA health care services via briefings, public presentations, written communication materials, and publications.

## BACKGROUND

The Department of Veterans Affairs (VA) is the nation’s largest integrated healthcare system, providing care for millions of US military Veterans. Providing high quality care is a commitment VA makes to Veterans. Comparisons of VA-delivered care to care delivered in non-VA settings are central to assessing the quality of VA care. Prior reviews comparing outcomes between VA and non-VA care included data through 2014, and found that VA care performed similarly to or better than non-VA care in most, but not all, aspects of quality.^1–3^ Since that time, concerns about access to care led to the Veteran Access, Choice, and Accountability (“Choice”) Act of 2014, which allowed Veterans to seek medical care in the community if the VA was unable to schedule a visit within 30 days or if the Veteran lived greater than 40 miles from their closest VA. This program also required independent performance assessments of VA’s healthcare services related to access and available expertise.^4^ Choice Act funding ended in 2017 and was followed by the VA Maintaining Internal Systems and Strengthening Integrated Outside Networks (MISSION) Act of 2018 that further addressed concerns regarding Veteran access to care by expanding eligibility for VA-reimbursed community care (CC) options.^5^ These acts greatly expanded the potential for care delivered to Veterans and paid for by VA to be from community providers, raising additional questions about comparisons of quality of care. To address these gaps and update the understanding outcomes of Veteran care, we conducted a systematic review to compare quality and safety, access, patient experience, and cost between VA and non-VA care.