# EXECUTIVE SUMMARY

Key Findings

- This review identified 53 relevant studies published between 2015 and 2023 that assessed the quality of VA care with the quality of non-VA care; 19 studies of surgical care and 38 studies of non-surgical care. Four studies contributed data to both.
- In the domain of quality and safety, the great majority of studies found that VA care is as good as, or better than, care in the community.
- For the domains of access, patient experience, and efficiency/cost, comparative studies were fewer in number and more mixed in results, but tended to favor VA care.

## INTRODUCTION

The Department of Veterans Affairs (VA) Veterans Health Administration (VHA) is the nation’s largest integrated healthcare system. Comparing the quality of VA-delivered healthcare to care delivered in non-VA settings is one way of ensuring VA maintains its commitment to providing high-quality care to Veterans. To support this aim, the VA’s Evidence Synthesis Program (ESP) systematically reviews studies comparing the quality of VA and non-VA healthcare. This systematic review is frequently updated with the most recently available evidence; the current report was previously updated in February 2023.

## METHODS

### Data Sources and Searches

We conducted broad searches using terms relating to Veterans health and community health services or private sector. To identify articles relevant to the key questions, a research librarian searched PubMed, APA PsycINFO, and Web of Science (1/1/2015–3/15/2023).

### Study Selection

Studies were included at either the abstract or the full-text level if they were original research studies of any design and made comparisons about the quality of care provided in VA Medical Centers and outpatient clinics compared with care provided in other health systems, ie, the general population. We included as quality any outcomes within the Institute of Medicine 6 domains of health care: quality, safety, access, patient experience, efficiency (cost), and equity.

### Data Abstraction and Assessment

Data were collected by 2 reviewers working independently with consensus resolution of disagreements.

### Synthesis

The synthesis is narrative.

## RESULTS

### Results of Literature Search

From 2,415 titles, we identified 38 studies of non-surgical care meeting inclusion criteria. From 2,408 titles, we identified 19 studies of surgical care meeting inclusion criteria. Four studies contributed data to both.

### Summary of Results for Key Questions

The results of our assessment are presented in the bubble plots below, 1 for nonsurgical care and 1 for surgical care. Both plots are organized the same way: the domains of care are listed on the horizontal axis (quality/safety, access, patient experience, cost/efficiency), the results of the study are listed on the vertical axis (VA care is better than community care, VA care and community care are about equal, or results are mixed, and community care is better than VA care), and then each study is entered as a shape, with larger shapes being studies of better quality and representativeness than studies depicted by smaller shapes. The color of the shape indicates the type of comparison: blue for studies comparing Veterans getting care from VA to Veterans getting VA-paid care in the community; orange for studies comparing Veterans getting care from VA and non-Veterans, or a general population, getting care in the community; and yellow for studies comparing Veterans getting care from VA to Veterans getting community care not paid by VA. Next to each shape is a brief thumbnail of what the study was about, and inside the shape is the year of publication (’18 = 2018, ’19 = 2019, etc).

ES Figure 1 Non-surgical Map

ES Figure 2 Surgical Map

## DISCUSSION

### Key Findings

Our systematic review identified 38 studies on non-surgical care and 19 studies of surgical care comparing quality, safety, access, patient experience, or efficiency/cost between VA-delivered care and non-VA-delivered care. The large majority of studies assessed quality and safety, followed by comparisons of access to care. Few studies—only 7 and 10, respectively—assessed patient experience or cost/efficiency. We found no studies comparing VA to non-VA care on equity.

In the domain of quality and safety, the great majority of studies found that VA care is as good as, or better than, care in the community. This was the case for both surgical care and non-surgical care, and for community care of Veterans and community care of non-Veterans. For the domains of access and of cost/efficiency, the studies were more evenly distributed between the categories of VA care is better, VA and community care are about the same, and community care is better. The few studies of patient experience found that VA care and community care were about the same, or VA care was better. We did not identify any study the found that patient experience was better in community care. With only 1 exception in both the surgical and the non-surgical studies, VA-delivered care was as good as or better than Veterans received from VA-paid community care.

### Future Research

We did not identify any studies comparing care for some conditions for which the MISSION act has resulted in increased community care, such as Physical Medicine and Rehabilitation.

### Conclusions

In general, most published studies of comparisons of quality of care show that Veterans getting care from VA get the same or better quality care than Veterans getting community care or the general public getting non-VA care.