# APPENDIX J PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 7 | Yes | Thank you.
7 | 8 | Yes | Thank you.
8 | 10 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
9 | 1 | No | Thank you.
10 | 2 | No | Thank you.
11 | 3 | No | Thank you.
12 | 4 | No | Thank you.
13 | 5 | No | Thank you.
14 | 7 | No | Thank you.
15 | 8 | No | Thank you.
16 | 10 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
17 | 1 | No | Thank you.
18 | 2 | No | Thank you.
19 | 3 | No | Thank you.
20 | 4 | No | Thank you.
21 | 5 | Yes - Recent JAMA Open Network paper on wait times in VA and Community Care by Feyman et al. | This has been added to the report and map.
22 | 7 | No | Thank you.
23 | 8 | No | Thank you.
24 | 10 | No | Thank you.
Additional suggestions or comments can be provided below.
25 | 1 | Overall this is an excellent review of the literature comparing VA to non VA care. The authors have divided the available studies into surgical and non surgical care, and divided the outcomes according to standard health services research categories. I was particularly glad to see that more studies are now available outside of quality and safety. The summary figure is very useful and will no doubt be very informative to policy makers. | Thank you for your comment.
26 | 1 | The search methods were quite thorough and I have little doubt that they have found all the relevant published literature. The inclusion criteria are very reasonable. I have some curiosity about whether the few excluded lower quality (fatal flaw) studies tended in the same direction of equal or better VA care overall, but in the end I think it is probably better that the authors did not spend time in sensitivity analyses in that direction. | We have now added information about these fatal flaw studies.
27 | 1 | Most of my suggestions revolve around interpretation. I would give more valence to more recent studies as the both the VA and non VA system are evolving over time. The last paragraph of the discussion covers the difference between the pre2015 and post2015 studies. I would have liked a bit more detail those differences. | We have now called out in each text section those studies specifically about the CHOICE/MISSION act comparisons, which are most of the more recent studies, and the comparison of greatest policy interest.
28 | 1 | Similarly there were innovative recent studies that probably deserve more highlighting. Observational studies are of course always subject to bias, and the authors do a great job of assessing how robust the individual studies are. However the recent Chan study on mortality was particularly interesting in that it used a novel instrumental variable and was directed at a particularly important outcome - mortality. There were only a handful of other mortality studies in either surgical or nonsurgical care, and by the description provided all of narrower scope or poorer quality. I would have like to see a paragraph or at least a statement on how this key outcome compared. | Unfortunately the Chan study was the only one if its kind. We have beefed up and discussed in more detail that the #1 limitation to all studies is the possibility of unmeasured confounding. I don’t think we can do better than that.
29 | 1 | Finally it is important to note that almost all the studies covered only a single or small subset of conditions. Thus the overall conclusion about VA care could be limited to those conditions and that might be noted. | This has been added to the Limitations.
30 | 2 | Well conducted review. Limitation of what’s available is noteworthy. Looking at the surgical topics, the specialty areas are focused on specific operations/diseases eg. lung resection for NSC; or kidney transplant. These clearly are important, but are probably not the common bread/butter operations that all the VA surgical care address. | This has been added to the Limitations.
31 | 3 | An obvious limitation is that the data do not provide insights on social challenges of veteran patients that are exacerbated by receiving care in a VHA facility that can influence hospital length of stay following surgery (e.g. availability of family/friend to take home when meeting discharge criteria). | This has been added to the Limitations.
32 | 4 | Page 14, lines 20–21. One of the main impetus for carrying out this evidence synthesis was to evaluate the quality of care Veterans receive in the community following passage of the Choice (2014) and MISSION (2018) Acts. And the authors were tasked with categorizing studies based on whether Veterans received care at a VA facility as opposed to a community facility through the Choice and MISSION Acts. However, a lot of the studies included in this summary had analyzed data that pre-dated the Choice and MISSION Acts. It would be nice to have some delineation or header in the manuscript for studies that specifically analyzed data after passage of the Choice legislation starting in 2014/2015. | We have now separated out in the map and the text the studies that are about non-VA care received as part of the CHOICE or MISSION Act.; Given that we identified some studies that compared VA care to VA-paid community care that preceded the CHOICE Act, we grouped all of these into a category now called “compared to Veterans getting VA-paid community care”
33 | 4 | Page 15, line 24: Was ‘Timing’ defined by publication date or when data was collected. As mentioned above, it appears that a lot of data included in this evidence synthesis was collected prior to 2015. | Timing was publication date as this update was intended to pick up the evidence where the last systematic review stopped.
34 | 4 | Page 21, line 60. I was wondering why cardiovascular revascularization procedures were included in KQ#1 group as opposed to KQ#2. It might make more sense to group all interventional procedures in the surgical group. | We agree that this is one potential classification system, but elected to keep the organization consistent with the prior 2012 review, which classified studies into surgery vs non-surgery (medical).
35 | 4 | Page 24, line 45: There is a typo; delete “for”. | This has been fixed, thank you.
36 | 4 | Page 27, line 46: I am curious why the authors included “Hospital Patient Safety Indicators and Outpatient Quality of Care” studies under the Patient Experience heading. It seems out of place. | This paragraph about these two studies was inadvertently placed in Patient Experience. It has now been moved to where it belongs in Quality and Safety.
37 | 5 | In general, this is a succinct, clearly written report. The organization is clear, the methods seem appropriate and the conclusions generally sound. I have inserted a number of comments directly in the report but have 4 general observations/suggestions: | Thank you for your comments.
38 | 5 | 1. The report describes two general types of studies: comparisons restricted to Veterans getting care in VA or non-VA setting, and comparisons of VA outcomes to general population outcomes. In fact there are further differences. In the first category, there are studies comparing enrolled veterans who get care in VA or VA-paid care provided outside VA through Community Care/choice/contracted care. There are also studies comparing outcomes of dually eligible veterans who get care in VA vs in Medicare. Among the second group of studies, there are studies where comparison population are all insured (Medicare, Medicaid or HMO comparisons) and others where the population comparisons are non-VA hospital patients who include a mix of insured and uninsured. | We have now split out the studies of comparison to CHOICE/MISSION Act care.
39 | 5 | 2. The report gives insufficient attention to the challenges in comparing quality and outcomes based on available data and how various sources of bias will vary based on the populations being compared and the outcomes used. I would have preferred more comment on the adequacy of efforts to control for clinical factors – if this was part of the evaluation of methods in the bias assessment it should be stated more clearly. The ability to adequately control for clinical and sociodemographic factors that affect clinical outcomes like mortality and readmission will vary substantially if some of the records are Medicare or private health systems. The cleanest comparisons are those that use Veteran populations and compare care in VA to that bought outside VA for the same patients, since both populations are insured, have comparable data, and are using the VA. For studies comparing enrolled Veterans getting VA care vs Medicare, there are selection factors that lead to greater VA or greater Medicare use that can bias outcomes. For some outcomes, claims level data may be adequate but for others such as CHF and MI, severity may vary by the source of care. Perhaps this is less than an issue than I worry, but some discussion should be included about what we know about the severity of illness and comorbidity of Veterans who get care in VA and those who get care in Medicare, or of Veterans vs. general Medicare population. Similarly, comparing VA hospital outcomes to private hospitals will be affected by the comorbidity of patient populations and sociodemographics. Readmissions may be driven by patients who are uninsured with poor social supports. | The issue of comparability has been added to the Limitations.
40 | 5 | 3. Table D on the medical care studies is confusing and spars in the data. Table E is much better organized and it would be preferable that Table D be reformatted in that manner. At a minimum, better description of the PICOTs elements for each study should be included at the beginning before listing all the individual outcome comparisons. | This has been reformatted.
41 | 5 | 4. The conclusions should spend a little more time in discussing the potential uses of this data and which comparisons might be most useful. First, comparisons are useful in identifying possible quality issues where VA performance should be improved. Looking at specific outcomes is important. Second, comparisons of VA vs Community Care are critical to shaping decisions about the expansion of that program and determining whether sending Veterans out for care in an effort to improve timeliness or convenience comes as a cost in terms of clinical outcomes. Third, some comparisons are useful at judging the potential advantages of the VA’s national system of integrated care vs. care delivery in less organized settings – eg delivery of preventive care and control of chronic disease. | This has been added to the Discussion.
42 | 5 | 5. Recommendations for research are underdeveloped. | This has been fixed.
43 | 5 | Page 16, Line 11: What about studies ability to adjust for differences in patient population -- eg underlying health status? If you didnt include this perhaps state why. | Adjusting for differences in patient population was one of the factors considered in “appropriate statistical methods”. We have added this to the text.
44 | 5 | Literature Flow: Is it meant to be “…Clinical Care in VA…” | This has been fixed.
45 | 5 | Literature Flow: Same error here: …Quality of clinical CARE… | This has been fixed.
46 | 5 | Page 22, Line 46: Did this study adjust for HF severity? | This study was not able to adjust for HF severity, only for the presence or absence of multiple comorbidities. We added this information to the text, and noted in the Limitations that the inability to control for things like this is a problem.
47 | 5 | Page 23, Line 11: The nursing home populations are very different in VA and non- VA settings, especially by gender, age and presence of dementia. The ability to adjust for these differences will depend on the outcome being assessed. | We have added to the text the variables that were used in adjustments.
48 | 5 | Page 23, Line 31: What risk factors were adjusted for? | We have added to the text the variables that were used in adjustments.
49 | 5 | Page 23, Line 51: This sentence is potentially confusing -- I assume that is is a hazard ratio from a time-dependent model, but the point that it implies lower rates of transplant may be lost. I would clarify with a parenthetical phrase (lower rate of transplant) | We added this parenthetical phrase.
50 | 5 | Page 26, Line 40: Better? | We changed ‘higher’ to ‘better’.
51 | 5 | Page 26, Line 56: Is timing to transplant affected by the organ allocation system that VA does not control? | We do not know the answer to this question and the article itself does not provide information about this.
52 | 5 | Page 28, Line 4: Risk adjusted readmission? | Yes these are risk-adjusted and we have added that to the text.
53 | 5 | Page 36, Line 35: Length of stay in VA can be driven by problems with nursing home placements. While this is a relevant indication of a problem it is different than if it were due to other factors. | This is acknowledged but nevertheless, the data are what they are and are compatible with the experience of VA clinicians on the inpatient service: length of stay is much longer in VA due to disposition challenges.
54 | 5 | Page 36, Line 60: I think more needs to be said about the ability of individual studies to account for differences in study populations, differences in who seeks community care, etc. These differences paly out differently depending on study design and outcome. A study of CHF mortality that cant adjust for severity of CHF is prone to error. Can we say anything about the underlying comorbidity of VA vs, medicare patients? | This has been added to the Limitations.
55 | 7 | None
56 | 8 | This report is flawless from a standpoint of rigor and analysis. It is, however, a bit dense for busy policymakers. The bubble charts (a nice innovation) help but take a bit of time to absorb. I suggest 2 minor enhancements: | Thank you for your comment.
57 | 8 | 1. Include a “Pull Out Box” that quickly states what this new report adds. (I note that BMJ, Annals, MMWR have recently instituted these so check them out if you want to see what I‘m talking about) | We think the “Key Findings” box at the beginning of the Executive Summary does this.
58 | 8 | 2. To make the bubble charts easier to use, start with a set of instructions first (right now, the key is a footnote to the chart) that orient the user. (This may take a bit of trial and error and perhaps a willing “test audience”) | This set of instructions is contained in the text.
59 | 10 | This evidence synthesis report updates prior comparisons of the quality of VA and non-VA care to include those published between 2015 to 2021. The comparisons were grouped under the broad category of non-surgical and surgical care - again in line with previously published evaluations. The search strategy appeared comprehensive and the studies were graded in a rigorous manner. I think this was a well-done synthesis. | Thank you for your comment.
60 | 10 | Main suggestions: 1) One of the key conclusions is as follows: “In the domain of quality and safety, the great majority of studies found that VA care is as good as, or better than, care in the community.” While this is a reasonable summary, I view “better than” to be fundamentally distinct from “as good as”. I would consider whether this distinction should be made in the abstract/executive summary. Ie, XXX studies demonstrated the VA was better than, YYY sudies showed the VA was as good as, and ZZZ studies showed the VA delivered worse …” This grouping would align better with the evidence maps that bucketed studies into the following groupings: “VA care is better”, “VA and community have equal or mixed results”, and “community care is better”. | We considered adding this….but ultimately elected not to do so, because it may make casual readers assume that we – the authors – are giving equal weight to each study, which we aren’t doing.
61 | 10 | 2) Although there was a lot of appropriate description of the validity of the studies and grading the quality of the research among a number of dimensions. I wonder if the research team included the importance of the outcome or quality measure in its assessment. In otherwords, some measures - like mortality and patient ratings of care - have strong face validity as important indicators of quality. For others - like length of stay and costs, it is not clear whether these actually represent quality measures (vs undefined metrics of resource utilization), whether lower is necessarily better, or whether they are appropriately risk-adjusted - particularly for critical factors like social support, function, or availability of stable housing. | This is a great question and one we discussed extensively. The problem is that if we, the research team, picks “importance” it is necessarily a subjective assessment. While at the extremes this may not be controversial—the example given of mortality compared to length of stay—other distinctions might be more controversial: for example, which is more important? Wait times for a urology appointment versus length-of-stay following joint replacement surgery? Because we did not think we could draw a bright and defensible line between important and less important outcomes, we elected to put them all in without an “importance” qualfier. But we did add to the Limitations that some outcomes will be more important than others and that this may vary by stakeholder.
62 | 10 | 3) There were five studies excluded because of ‘fatal flaws”. Would consider adding a brief description of the fatal flaw to exhibit B - similar to what was done in Exhibit C to describe why each studies did not meet inclusion criteria. | This was probably a bad use of jargon on our part. We have re-named them for what they are: unrepresentative samples, most single provider or single site studies.
63 | 10 | 4) It is unclear why studies of travel distance were included in this review. Longer travel distances for Veterans receiving some kinds of care (ie transplant) compared to non-Veterans may relate to decisions about whether VA patients are more likely to live in rural locations and the fact that the VA serves a subset of military veterans in ~130 centers whereas community care by definition includes the entire US population and all clinical facilities. | Travel distance was included in the review because it was in CHOICE as a criterion. We have added to the Limitations that travel distance may be of differing importance to different stakeholders.
64 | 10 | 5) In grading the quality of the evidence, did the authors consider the appropriateness of the risk-adjustment models? Many of the studies that examine mortality and readmission rely on claims-based approaches and compare outcome in the VA with that in Medicare. Given the incentives for private providers to overcode comorbidities, this kind of approach may penalize the VA since Medicare or private-sector patients would be labeled as being sicker. If some comparisons include a more comprehensive (and less “gameable”) set of risk-adjustment variables, perhaps they should be called out as being stronger. | This is a great comment and something we tried to assess but have added to the limitations that for some it is impossible (like the upcoding in FFS medicine).