# APPENDIX G SURGICAL RISK OF BIAS TABLE

Author, Year | Time Frames | Samples (Both VA and Non-VA) | How Did the Specifications for the Outcome Assessments Compare in VA and Non-VA Samples? | Statistical Methods
Harris, 2021^60^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Pettey, 2021^55^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Rosen, 2021^47^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Wagner, 2021^56^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Sufficiently similar for valid comparison | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Heiden, 2021^57^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Sufficiently similar for valid comparison | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Billig, 2021^46^ | Contemporaneous time frames | Small, limited, unequal or non-representative samples | Identical | All between A and C
Griffith, 2020^38^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Kesseli, 2020^52^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Rosen, 2020^61^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Eid, 2020^45^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Frisch, 2020^48^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Williams, 2020^51^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Augustine, 2018^9^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Wu, 2018^54^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Barnett, 2018^19^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Sufficiently similar for valid comparison | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Blay, 2017^28^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Hutt, 2015^50^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Sufficiently similar for valid comparison | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
George, 2021^59^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Sufficiently similar for valid comparison | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Mull, 2022^53^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)