# APPENDIX F NON-SURGICAL RISK OF BIAS TABLE

Author, Year | Time Frames | Samples (Both VA and Non-VA) | How Did the Specifications for the Outcome Assessments Compare in VA and Non-VA Samples? | Statistical Methods
Nuti, 2016^20^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Vanneman, 2020^40^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Gurewich, 2021^37^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Davila, 2021^41^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Intrator, 2021^22^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
LaBedz, 202130 | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Gidwani, 2021^43^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Griffith, 2020^38^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Gidwani-Marszowski, 2020^34^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Penn, 2019^36^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Makarov, 2018^42^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Wang, 2019^24^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Thorpe, 2018^21^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Vercammen-Grandjean, 2018^31^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Wang, 2018^25^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Augustine, 2018^9^ | Contemporaneous time frames | All between A and C | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Anhang Price, 2018^29^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Kurella Tamura, 2018^26^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Barnett, 2018^19^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Heidenreich, 2017^14^ | Contemporaneous time frames | All between A and C | Identical | All between A and C
Blay, 2017^28^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Mody, 2017^15^ | Contemporaneous time frames | All between A and C | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Shields, 2017^17^ | Contemporaneous time frames | All between A and C | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Burke, 2016^10^ | Contemporaneous time frames | Small, limited, unequal or nonrepresentative samples | Identical | Insufficient sample size and/or methods questionable to address hypothesis(ses)
Lee, 2017^11^ | Contemporaneous time frames | All between A and C | Identical | All between A and C
Axon, 2016^16^ | Contemporaneous time frames | All between A and C | Identical | All between A and C
Jia, 2016^23^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Watkins, 2016^32^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Jones, 2015^7^ | Contemporaneous time frames | All between A and C | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Chan, 2022^58^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Florez, 2021^8^ | Contemporaneous time frames | All between A and C | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Feyman, 2022^39^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Cashion, 2021^27^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Presley, 2022^18^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | All between A and C
Pickering, 2022^44^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Fortney, 2022^12^ | Contemporaneous time frames | All between A and C | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Scheuner, 2022^35^ | Contemporaneous time frames | Representative or national samples (both VA and non-VA) | Identical | Sufficient sample size and/or methods appropriate to address hypothesis(ses)
Petros, 2022^13^ | Contemporaneous time frames | All between A and C | Identical | All between A and C