# APPENDIX C EXCLUDED STUDIES

## NON-SURGICAL EXCLUDES

### Does Not Compare Quality of Clinical Data in VA and US Non-VA Settings, N = 51

1 Augustine, M.R., , Reasons Older Veterans Use the Veterans Health Administration and Non-VHA Care in an Urban Environment. J Am Board Fam Med, 2021. 34(2): p. 291–300.33832997
2 Benzer, J.K., , Survey of Patient-Centered Coordination of Care for Diabetes with Cardiovascular and Mental Health Comorbidities in the Department of Veterans Affairs. Journal of General Internal Medicine, 2019. 34(1): p. 43–49.31098975
3 Bouldin, E.D., , Medicare-VHA dual use is associated with poorer chronic wound healing. Wound Repair Regen, 2016. 24(5): p. 913–922.27292283
4 Burke, J.F. and Callaghan B.C., Author response: Neuroimaging overuse is more common in Medicare compared with the VA. Neurology, 2017. 88(6): p. 608.
5 Dayoub, E.J., , Federal Payments for Coronary Revascularization Procedures Among Dual Enrollees in Medicare Advantage and the Veterans Affairs Health Care System. JAMA Netw Open, 2020. 3(4): p. e201451.32250432
6 Desmarais, J. and Chu C.Q., Utility of Anakinra in Acute Crystalline Diseases: A Retrospective Study Comparing a University Hospital with a Veterans Affairs Medical Center. J Rheumatol, 2019. 46(7): p. 748–750.30442822
7 Feyman, Y., Legler A., and Griffith K.N., Appointment wait time data for primary & specialty care in veterans health administration facilities vs. community medical centers. Data Brief, 2021. 36: p. 107134.34095383
8 Gidwani-Marszowski, R., , Quality Of End-Of-Life Care Is Higher In The VA Compared To Care Paid For By Traditional Medicare. Health Aff (Millwood), 2018. 37(1): p. 95–103.29309227
9 Griebling, T.L., Re: Comparing Catheter-Associated Urinary Tract Infection Prevention Programs between Veterans Affairs Nursing Homes and Non-Veterans Affairs Nursing Homes. J Urol, 2018. 200(6): p. 1142.
10 Hebert, P.L., , Reliance on Medicare Providers by Veterans after Becoming Age-Eligible for Medicare is Associated with the Use of More Outpatient Services. Health Serv Res, 2018. 53 Suppl 3(Suppl Suppl 3): p. 5159–5180.30175401
11 Johnston, J.C. and Sartwelle T.P., Letter re: Neuroimaging overuse is more common in Medicare compared with the VA. Neurology, 2017. 88(6): p. 608.
12 Jones, A.L., , National Media Coverage of the Veterans Affairs Waitlist Scandal: Effects on Veterans’ Distrust of the VA Health Care System. Med Care, 2021. 59(Suppl 3): p. S322–S326.33976083
13 Leonard, C., , Operationalizing an Implementation Framework to Disseminate a Care Coordination Program for Rural Veterans. Journal of General Internal Medicine, 2019. 34(1): p. 58–66.
14 Lewinski, A.A., , Applied Rapid Qualitative Analysis to Develop a Contextually Appropriate Intervention and Increase the Likelihood of Uptake. Med Care, 2021. 59(Suppl 3): p. S242–S251.33976073
15 Loganathan, S.K., , Racial and Ethnic Differences in Satisfaction with Care Coordination Among VA and non-VA Medicare Beneficiaries. Health Equity, 2017. 1(1): p. 50–60.30283835
16 Machlin S.R. and Muhuri P., Characteristics and Health Care Expenditures of VA Health System Users versus Other Veterans, 2014–2015 (Combined), in Statistical Brief (Medical Expenditure Panel Survey (US)). 2001, Agency for Healthcare Research and Quality (US): Rockville (MD).
17 Malhotra A., Vaughan-Sarrazin M., and Rosenthal G.E., Elderly veterans with dual eligibility for VA and Medicare services: where do they obtain a colonoscopy? Am J Manag Care, 2015. 21(4): p. e264–70.26244789
18 Mattocks K.M., , Understanding Maternity Care Coordination for Women Veterans Using an Integrated Care Model Approach. Journal of General Internal Medicine, 2019. 34(1): p. 50–57.31098973
19 McCreight M.S., , Practical Use of Process Mapping to Guide Implementation of a Care Coordination Program for Rural Veterans. Journal of General Internal Medicine, 2019. 34(1): p. 67–74.31098974
20 Mohr D.C., , Organizational Coordination and Patient Experiences of Specialty Care Integration. Journal of General Internal Medicine, 2019. 34(1): p. 30–36.31098971
21 Mudumbai S.C., , Perioperative Opioid Prescribing Patterns and Readmissions After Total Knee Arthroplasty in a National Cohort of Veterans Health Administration Patients. Pain Med, 2020. 21(3): p. 595–603.31309970
22 Nadpara P.A., , Risk Factors for Serious Prescription Opioid-Induced Respiratory Depression or Overdose: Comparison of Commercially Insured and Veterans Health Affairs Populations. Pain Med, 2018. 19(1): p. 79–96.28419384
23 Nelson R.E., , The Impact of a Change in the Price of VA Health Care on Utilization of VA and Medicare Services. Med Care, 2018. 56(7): p. 569–576.29768309
24 Nelson R.E., , Costs Associated with Health Care Services Accessed through VA and in the Community through Medicare for Veterans Experiencing Homelessness. Health Serv Res, 2018. 53 Suppl 3(Suppl Suppl 3): p. 5352–5374.30246368
25 Noël P.H., , Patient experience of health care system hassles: Dual-system vs single-system users. Health Serv Res, 2020. 55(4): p. 548–555.32380578
26 Nuti S.V., Qin L., and Krumholz H.M., Outcome After Admission at Veterans Affairs vs Non-Veterans Affairs Hospitals--Reply. Jama, 2016. 316(3): p. 346.
27 O’Hanlon C.E., Farmer C., and Gidengil C., Comparing VA to Non-VA Care. J Gen Intern Med, 2017. 32(2): p. 152.27761768
28 Olmos-Ochoa T.T., , Staff Perspectives on Primary Care Teams as De Facto “Hubs” for Care Coordination in VA: a Qualitative Study. Journal of General Internal Medicine, 2019. 34(1): p. 82–89.
29 Pershing S., , Treating age-related macular degeneration: comparing the use of two drugs among medicare and veterans affairs populations. Health Aff (Millwood), 2015. 34(2): p. 229–38.25646102
30 Peterson K., , Health Care Coordination Theoretical Frameworks: a Systematic Scoping Review to Increase Their Understanding and Use in Practice. Journal of General Internal Medicine, 2019. 34(1): p. 90–98.
31 Radomski T.R., Fine M.J., and Gellad W.F., Outcome After Admission at Veterans Affairs vs Non-Veterans Affairs Hospitals. Jama, 2016. 316(3): p. 345–6.27434448
32 Radomski T.R., , The Impact of Medication-Based Risk Adjustment on the Association Between Veteran Health Outcomes and Dual Health System Use. J Gen Intern Med, 2017. 32(9): p. 967–973.28462490
33 Ramkumar M. and Crowley S.T., Kidney Transplantation Rates of Veterans Administration-Listed Patients Compared with Rates of Patients on Nonveteran Lists. J Am Soc Nephrol, 2018. 29(10): p. 2449–2450.30228151
34 Rinne S.T., , VA Provider Perspectives on Coordinating COPD Care Across Health Systems. Journal of General Internal Medicine, 2019. 34(1): p. 37–42.31011970
35 Rose D.E., , Variations in VA and Medicare Use Among Veterans With Diabetes: Impacts on Ambulatory Care Sensitive Conditions Hospitalizations for 2008, 2009, and 2010. Med Care, 2019. 57(6): p. 425–436.31045693
36 Rose L., , Association of Expanded Health Care Networks With Utilization Among Veterans Affairs Enrollees. JAMA Netw Open, 2021. 4(10): p. e2131141.34698845
37 Rosenberg K., End-Of-Life Cancer Care For Veterans Through The VA Vs. Medicare. Am J Nurs, 2018. 118(5): p. 70.29698288
38 Trivedi A.N., , Dual Use and Hospital Admissions among Veterans Enrolled in the VA’s Homeless Patient Aligned Care Team. Health Serv Res, 2018. 53 Suppl 3(Suppl Suppl 3): p. 5219–5237.30151996
39 Trivedi A.N., , Agreement Between HEDIS Performance Assessments in the VA and Medicare Advantage: Is Quality in the Eye of the Beholder? Inquiry, 2016. 53.
40 Tummalapalli S.L. and Keyhani S., Trends in Preventative Health Services for Veterans with Military Coverage Compared to Non-Military Coverage. J Gen Intern Med, 2020. 35(4): p. 1330–1333.31621048
41 Valle J.A., , Dual antiplatelet therapy in non-ST elevation acute coronary syndromes at Veterans Affairs Hospitals. Heart, 2019. 105(20): p. 1575–1582.31092547
42 Veet C.A., , Impact of Healthcare Delivery System Type on Clinical, Utilization, and Cost Outcomes of Patient-Centered Medical Homes: a Systematic Review. J Gen Intern Med, 2020. 35(4): p. 1276–1284.31907790
43 Ward R., , An Evaluation of Statin Use Among Patients with Type 2 Diabetes at High Risk of Cardiovascular Events Across Multiple Health Care Systems. J Manag Care Spec Pharm, 2020. 26(9): p. 1090–1098.32857659
44 Weeks W.B., Comparing VA to Non-VA Care. J Gen Intern Med, 2017. 32(2): p. 150–151.27730485
45 Wong E.S., , Impact of VHA’s primary care intensive management program on dual system use. Healthc (Amst), 2020. 8(3): p. 100450.32919588
46 Wray C.M., Khare M., and Keyhani S., Access to Care, Cost of Care, and Satisfaction With Care Among Adults With Private and Public Health Insurance in the US. JAMA Netw Open, 2021. 4(6): p. e2110275.34061204
47 Wray C.M., Lopez L., and Keyhani S., "Comparing VA and Non-VA Care Quality". J Gen Intern Med, 2019. 34(4): p. 485.30543019
48 Yoon J., , Use of the Veterans’ Choice Program and Attrition From Veterans Health Administration Primary Care. Med Care, 2020. 58(12): p. 1091–1097.32925455
49 Yu M.K., , Trends in Timing of Dialysis Initiation within Versus Outside the Department of Veterans Affairs. Clin J Am Soc Nephrol, 2015. 10(8): p. 1418–27.26206891
50 Zulman D.M, , Effects of Intensive Primary Care on High-Need Patient Experiences: Survey Findings from a Veterans Affairs Randomized Quality Improvement Trial. Journal of General Internal Medicine, 2019. 34(1): p. 75–81.
51 Gaffney A., , Uptake and Equity in Influenza Vaccination Among Veterans with VA Coverage, Veterans Without VA Coverage, and Non-Veterans in the USA, 2019–2020. J Gen Intern Med, 2022: p. 1–8.

### Not Research, N = 7

1 Cordasco K.M., , Coordinating Care Across VA Providers and Settings: Policy and Research Recommendations from VA’s State of the Art Conference. Journal of General Internal Medicine, 2019. 34(1): p. 11–17.31098966
2 Cordasco K.M., , Improving Care Coordination for Veterans Within VA and Across Healthcare Systems. Journal of General Internal Medicine, 2019. 34(1): p. 1–3.
3 Gittell J.H. and Hajjar L., Strengthening Patient-Centered Care in the VHA: A Relational Model of Change. Journal of General Internal Medicine, 2019. 34(1): p. 7–10.
4 Mattocks K.M., , Recommendations for the Evaluation of Cross-System Care Coordination from the VA State-of-the-art Working Group on VA/Non-VA Care. Journal of General Internal Medicine, 2019. 34(1): p. 18–23.31098968
5 Mattocks K.M., , Innovations in Community Care Programs, Policies, and Research. Med Care, 2021. 59(Suppl 3): p. S229–S231.33976071
6 McDonald K.M., , Incorporating Theory into Practice: Reconceptualizing Exemplary Care Coordination Initiatives from the US Veterans Health Delivery System. Journal of General Internal Medicine, 2019. 34(1): p. 24–29.31098965
7 Mengeling M.A., , Partnership Forum: The Role of Research in the Transfonnation of Veterans Affairs Community Care. Med Care, 2021. 59(Suppl 3): p. S232–S241.33976072

### Background, N = 6

1 Garvin L.A., , Interorganizational Care Coordination of Rural Veterans by Veterans Affairs and Community Care Programs: A Systematic Review. Med Care, 2021. 59(Suppl 3): p. S259–S269.33976075
2 Gordon S.H., , County-level Predictors of Growth in Community-based Primary Care Use Among Veterans. Med Care, 2021. 59(Suppl 3): p. S301–S306.33976080
3 Greenstone C.L., , Standardizing Care Coordination Within the Department of Veterans Affairs. Journal of General Internal Medicine, 2019. 34(1): p. 4–6.31098969
4 Hynes D.M., , Veterans’ Use of Veterans Health Administration Primary Care in an Era of Expanding Choice. Med Care, 2021. 59(Suppl 3): p. S292–S300.33976079
5 Mattocks K.M., , Understanding VA’s Use of and Relationships With Community Care Providers Under the MISSION Act. Med Care, 2021. 59(Suppl 3): p. S252–S258.33976074
6 Vashi A.A., , Community Urgent Care Use Following Implementation of the Veterans Affairs Maintaining Internal Systems and Strengthening Integrated Outside Networks Act. Med Care, 2021. 59(Suppl 3): p. S314–S321.33976082

### About Surgery, N = 5

1 Billig J.I., , The Impact of Community Care Referral on Time to Surgery for Veterans With Carpal Tunnel Syndrome. Med Care, 2021. 59(Suppl 3): p. S279–S285.33976077
2 George E.L., , Comparing Veterans Affairs and Private Sector Perioperative Outcomes After Noncardiac Surgery. JAMA Surg, 2021.
3 Harris A.H.S., , Comparing Complication Rates After Elective Total Knee Arthroplasty Delivered Or Purchased By The VA. Health Aff (Millwood), 2021. 40(8): p. 1312–1320.34339235
4 Pettey W.B.P., , Comparing Driving Miles for Department of Veterans Affairsdelivered Versus Department of Veterans Affairs-purchased Cataract Surgery. Med Care, 2021. 59(Suppl 3): p. S307–S313.33976081
5 Rosen A. K., Beilstein-Wedel E. E., Harris A. H. S., Shwartz M., Vanneman M. E., Wagner T. H. and Giori N. J. (2022). "Comparing Postoperative Readmission Rates Between Veterans Receiving Total Knee Arthroplasty in the Veterans Health Administration Versus Community Care." Med Care 60(2): 178–186.35030566

### Unrepresentative Samples or Comparisons, N = 5

1 Bartel M.J., Robertson D.J., and Pohl H., Colonoscopy practice for veterans within and outside the Veterans Affairs setting: a matched cohort study. Gastrointest Endosc, 2016. 84(2): p. 272–8.26784365
2 Chao D., , Outcomes Comparison of the Veterans’ Choice Program With the Veterans Affairs Health Care System for Hepatitis C Treatment. Fed Pract, 2020. 37(Suppl 3): p. S18–s24.
3 Cullen S.W., , Comparing Rates of Adverse Events and Medical Errors on Inpatient Psychiatric Units at Veterans Health Administration and Community-based General Hospitals. Med Care, 2019. 57(11): p. 913–920.31609847
4 Dueker J.M. and Khalid A., Performance of the Veterans Choice Program for Improving Access to Colonoscopy at a Tertiary VA Facility. Fed Pract, 2020. 37(5): p. 224–228.32454576
5 Grubbs K.M., , A Comparison of Collaborative Care Outcomes in Two Health Care Systems: VA Clinics and Federally Qualified Health Centers. Psychiatr Serv, 2018. 69(4): p. 431–437.29334874

### No Outcomes of Interest, N = 2

1 Dismuke-Greer C.E., , Economic impact of comorbid TBI-dementia on VA facility and non-VA facility costs, 2000–2020. Brain Inj, 2022. 36(5): p. 673–682.35099349
2 Wray C., , Digital Health Skillsets and Digital Preparedness: Comparison of Veterans Health Administration Users and Other Veterans Nationally. JMIR Form Res, 2022. 6(1): p.e32764.35089147

## SURGICAL EXCLUDES

### Does Not Compare Quality of Clinical Data in VA and US Non-VA Settings, N = 19

1 Benzer J.K., , Survey of Patient-Centered Coordination of Care for Diabetes with Cardiovascular and Mental Health Comorbidities in the Department of Veterans Affairs. Journal of General Internal Medicine, 2019. 34(1): p. 43–49.31098975
2 Billig J.I., , Surgical Timing for Carpal Tunnel Syndrome: A Comparison of Health Care Delivery in the Veterans Administration and Private Sector. J Hand Surg Am, 2021. 46(7): p. 544–551.33867201
3 Clarke E.L., , Association of Tumor Characteristics With Insurance Type Among Patients Undergoing Mohs Micrographic Surgery for Nonmelanoma Skin Cancer. JAMA Dermatol, 2022. 158(8): p. 919–922.35648411
4 Dayoub E.J., , Federal Payments for Coronary Revascularization Procedures Among Dual Enrollees in Medicare Advantage and the Veterans Affairs Health Care System. JAMA Netw Open, 2020. 3(4): p. e201451.32250432
5 Jones A.L., , National Media Coverage of the Veterans Affairs Waitlist Scandal: Effects on Veterans’ Distrust of the VA Health Care System. Med Care, 2021. 59(Suppl 3): p. S322–S326.33976083
6 Leonard C., , Operationalizing an Implementation Framework to Disseminate a Care Coordination Program for Rural Veterans. Journal of General Internal Medicine, 2019. 34(1): p. 58–66.
7 Lewinski A.A., , Applied Rapid Qualitative Analysis to Develop a Contextually Appropriate Intervention and Increase the Likelihood of Uptake. Med Care, 2021. 59(Suppl 3): p. S242–S251.33976073
8 Mattocks K.M., , Understanding Maternity Care Coordination for Women Veterans Using an Integrated Care Model Approach. Journal of General Internal Medicine, 2019. 34(1): p. 50–57.31098973
9 McCreight M.S., , Practical Use of Process Mapping to Guide Implementation of a Care Coordination Program for Rural Veterans. Journal of General Internal Medicine, 2019. 34(1): p. 67–74.31098974
10 Mohr D.C., , Organizational Coordination and Patient Experiences of Specialty Care Integration. Journal of General Internal Medicine, 2019. 34(1): p. 30–36.31098971
11 Mudumbai S.C., , Perioperative Opioid Prescribing Patterns and Readmissions After Total Knee Arthroplasty in a National Cohort of Veterans Health Administration Patients. Pain Med, 2020. 21(3): p. 595–603.31309970
12 Mull H.J., , Emergency Department Use After Outpatient Surgery Among Dually Enrolled VA and Medicare Patients. Qual Manag Health Care, 2019. 28(4): p. 191–199.31567842
13 Napolitano M.A., , Direct Comparison of Outcomes After Transcatheter Aortic Valve Replacement in Veterans and Non-Veterans Using the Transcatheter Valve Therapy Registry. J Invasive Cardiol, 2022. 34(8): p. E601–e610.35830359
14 Olmos-Ochoa T.T., , Staff Perspectives on Primary Care Teams as De Facto “Hubs” for Care Coordination in VA: a Qualitative Study. Journal of General Internal Medicine, 2019. 34(1): p. 82–89.
15 Peterson K., , Health Care Coordination Theoretical Frameworks: a Systematic Scoping Review to Increase Their Understanding and Use in Practice. Journal of General Internal Medicine, 2019. 34(1): p. 90–98.
16 Rinne S.T., , VA Provider Perspectives on Coordinating COPD Care Across Health Systems. Journal of General Internal Medicine, 2019. 34(1): p. 37–42.31011970
17 Shih L., , The Impact of Hospital-Based Systems on Plastic Surgery Resident Education: Veterans Affairs Medical Centers versus Public County Hospitals. Plast Reconstr Surg, 2020. 146(5): p. 707e-708e.
18 Valle J.A., , Dual antiplatelet therapy in non-ST elevation acute coronary syndromes at Veterans Affairs Hospitals. Heart, 2019. 105(20): p. 1575–1582.31092547
19 Zulman D.M., , Effects of Intensive Primary Care on High-Need Patient Experiences: Survey Findings from a Veterans Affairs Randomized Quality Improvement Trial. Journal of General Internal Medicine, 2019. 34(1): p. 75–81.

### Not About Surgery, N = 16

1 Carico R., , Receipt of Overlapping Opioid and Benzodiazepine Prescriptions Among Veterans Dually Enrolled in Medicare Part D and the Department of Veterans Affairs: A Cross-sectional Study. Ann Intern Med, 2018. 169(9): p. 593–601.30304353
2 Cashion W., , Source of Post-Transplant Care and Mortality among Kidney Transplant Recipients Dually Enrolled in VA and Medicare. Clin J Am Soc Nephrol, 2021. 16(3): p. 437–445.33602753
3 Chan D.C., , Mortality among US veterans after emergency visits to Veterans Affairs and other hospitals: retrospective cohort study. BMJ, 2022. 376: p. e068099.35173019
4 Davila H., , Rural Veterans’ Experiences With Outpatient Care in the Veterans Health Administration Versus Community Care. Med Care, 2021. 59(Suppl 3): p. S286–S291.33976078
5 Feyman Y., Asfaw D.A., and Griffith K.N., Geographic Variation in Appointment Wait Times for US Military Veterans. JAMA Netw Open, 2022. 5(8): p. e2228783.36006640
6 Florez H.J., , Differences in complications, cardiovascular risk factor, and diabetes management among participants enrolled at veterans affairs (VA) and non-VA medical centers in the glycemia reduction approaches in diabetes: A comparative effectiveness study (GRADE). Diabetes Res Clin Pract, 2021. 184: p. 109188.34971663
7 Griebling T.L., Re: Comparing Catheter-Associated Urinary Tract Infection Prevention Programs between Veterans Affairs Nursing Homes and Non-Veterans Affairs Nursing Homes. J Urol, 2018. 200(6): p. 1142.
8 Gurewich D., , Did Access to Care Improve Since Passage of the Veterans Choice Act?: Differences Between Rural and Urban Veterans. Med Care, 2021. 59(Suppl 3): p. S270–S278.33976076
9 LaBedz S.L., , Chronic Obstructive Pulmonary Disease Outcomes at Veterans Affairs Versus Non-Veterans Affairs Hospitals. Chronic Obstr Pulm Dis, 2021. 8(3): p. 306–313.33975417
10 Moyo P., , Dual Receipt of Prescription Opioids From the Department of Veterans Affairs and Medicare Part D and Prescription Opioid Overdose Death Among Veterans: A Nested Case-Control Study. Ann Intern Med, 2019. 170(7): p. 433–442.30856660
11 Nuti S.V., , Association of Admission to Veterans Affairs Hospitals vs Non-Veterans Affairs Hospitals With Mortality and Readmission Rates Among Older Men Hospitalized With Acute Myocardial Infarction, Heart Failure, or Pneumonia. JAMA, 2016. 315(6): p. 582–92.26864412
12 Rose L., , Association of Expanded Health Care Networks With Utilization Among Veterans Affairs Enrollees. JAMA Netw Open, 2021. 4(10): p. e2131141.34698845
13 Schuttner L., , Factors Associated With Low-Value Cancer Screenings in the Veterans Health Administration. JAMA Netw Open, 2021. 4(10): p. e2130581.34677595
14 The L., Privatising versus prioritising veterans’ health. Lancet, 2018. 391(10128): p. 1332.
15 Tummalapalli S.L. and Keyhani S., Trends in Preventative Health Services for Veterans with Military Coverage Compared to Non-Military Coverage. J Gen Intern Med, 2020. 35(4): p. 1330–1333.31621048
16 Vanneman M.E., , Veterans’ Experiences With Outpatient Care: Comparing The Veterans Affairs System With Community-Based Care. Health Aff (Millwood), 2020. 39(8): p. 1368–1376.32744943

### Not Research, N = 7

1 Loraasco K.M., , Loorainating vare Across va rroviaers ana settings: rottcy ana Research Recommendations from VA’s State of the Art Conference. Journal of General Internal Medicine, 2019. 34(1): p. 11–17.31098966
2 Cordasco K.M., , Improving Care Coordination for Veterans Within VA and Across Healthcare Systems. Journal of General Internal Medicine, 2019. 34(1): p. 1–3.
3 Gittell J.H. and Hajjar L., Strengthening Patient-Centered Care in the VHA: A Relational Model of Change. Journal of General Internal Medicine, 2019. 34(1): p. 7–10.
4 Mattocks K.M., , Recommendations for the Evaluation of Cross-System Care Coordination from the VA State-of-the-art Working Group on VA/Non-VA Care. Journal of General Internal Medicine, 2019. 34(1): p. 18–23.31098968
5 Mattocks K.M., , Innovations in Community Care Programs, Policies, and Research. Med Care, 2021. 59(Suppl 3): p. S229–S231.33976071
6 McDonald K.M., , Incorporating Theory into Practice: Reconceptualizing Exemplary Care Coordination Initiatives from the US Veterans Health Delivery System. Journal of General Internal Medicine, 2019. 34(1): p. 24–29.31098965
7 Mengeling M.A., , Partnership Forum: The Role of Research in the Transformation of Veterans Affairs Community Care. Med Care, 2021. 59(Suppl 3): p. S232–S241.33976072

### Background, N = 6

1 Garvin L.A., , Interorganizational Care Coordination of Rural Veterans by Veterans Affairs and Community Care Programs: A Systematic Review. Med Care, 2021. 59(Suppl 3): p. S259–S269.33976075
2 Gordon S.H., , County-level Predictors of Growth in Community-based Primary Care Use Among Veterans. Med Care, 2021. 59(Suppl 3): p. S301–S306.33976080
3 Greenstone C.L., , Standardizing Care Coordination Within the Department of Veterans Affairs. Journal of General Internal Medicine, 2019. 34(1): p. 4–6.31098969
4 Hynes D.M., , Veterans’ Use of Veterans Health Administration Primary Care in an Era of Expanding Choice. Med Care, 2021. 59(Suppl 3): p. S292–S300.33976079
5 Mattocks K.M., , Understanding VA’s Use of and Relationships With Community Care Providers Under the MISSION Act. Med Care, 2021. 59(Suppl 3): p. S252–S258.33976074
6 Vashi A.A., , Community Urgent Care Use Following Implementation of the Veterans Affairs Maintaining Internal Systems and Strengthening Integrated Outside Networks Act. Med Care, 2021. 59(Suppl 3): p. S314–S321.33976082

### Editorial, N = 5

1 Nuti S.V, Qin L., and Krumholz H.M., Outcome After Admission at Veterans Affairs vs Non-Veterans Affairs Hospitals--Reply. Jama, 2016. 316(3): p. 346.
2 O’Hanlon C.E., Farmer C., and Gidengil C., Comparing VA to Non-VA Care. J Gen Intern Med, 2017. 32(2): p. 152.27761768
3 Radomski T.R., Fine M.J., and Gellad W.F., Outcome After Admission at Veterans Affairs vs Non-Veterans Affairs Hospitals. Jama, 2016. 316(3): p. 345–6.27434448
4 Ramkumar M. and Crowley S.T., Kidney Transplantation Rates of Veterans Administration-Listed Patients Compared with Rates of Patients on Nonveteran Lists. J Am Soc Nephrol, 2018. 29(10): p. 2449–2450.30228151
5 Weeks W.B., Comparing VA to Non-VA Care. J Gen Intern Med, 2017. 32(2): p. 150–151.27730485

### Unrepresentative Samples or Comparisons, N = 2

1 Dizon M.P, , Comparing the Quality of Ambulatory Surgical Care for Skin Cancer in a Veterans Affairs Clinic and a Fee-For-Service Practice Using Clinical and Patient-Reported Measures. PLoS One, 2017. 12(1): p. e0171253.28141817
2 Geraci T., , Lobectomy for Lung Cancer at Veterans Administration Medical Center Versus Academic Medical Center. Ann Thorac Surg, 2017. 103(6): p. 1715–1722.28347532