# APPENDIX B LIST OF STUDIES WITH UNREPRESENTATIVE SAMPLES OR COMPARISONS

1 Bartel M. J., Robertson D. J. and Pohl H. (2016). "Colonoscopy practice for veterans within and outside the Veterans Affairs setting: a matched cohort study." Gastrointest Endosc 84(2): 272–278.26784365
2 Chao D., Buddha H., Damodaran C., Tran L., Strong R. and Jackson C. S. (2020). "Outcomes Comparison of the Veterans’ Choice Program With the Veterans Affairs Health Care System for Hepatitis C Treatment." Fed Pract 37(Suppl 3): S18–s24.
3 Cullen S. W., Xie M., Vermeulen J. M. and Marcus S. C. (2019). "Comparing Rates of Adverse Events and Medical Errors on Inpatient Psychiatric Units at Veterans Health Administration and Community-based General Hospitals." Med Care 57(11): 913–920.31609847
4 Dizon M.P., , Comparing the Quality of Ambulatory Surgical Care for Skin Cancer in a Veterans Affairs Clinic and a Fee-For-Service Practice Using Clinical and Patient-Reported Measures. PLoS One, 2017. 12(1): p. e0171253.28141817
5 Dueker J. M. and Khalid A. (2020). "Performance of the Veterans Choice Program for Improving Access to Colonoscopy at a Tertiary VA Facility." Fed Pract 37(5): 224–228.32454576
6 Geraci T., , Lobectomy for Lung Cancer at Veterans Administration Medical Center Versus Academic Medical Center. Ann Thorac Surg, 2017. 103(6): p. 1715–1722.28347532
7 Grubbs K. M., Fortney J. C., Pyne J., Mittal D., Ray J. and Hudson T. J. (2018). "A Comparison of Collaborative Care Outcomes in Two Health Care Systems: VA Clinics and Federally Qualified Health Centers." Psychiatr Serv 69(4): 431–437.29334874