# APPENDIX A SEARCH STRATEGIES

[underlined: PubMed]

[underlined: English; 2015 to Present]

[underlined: Search run: 9 March 2023]

"United States Department of Veterans Affairs"[mh] OR "Veterans Health"[mh] OR "veterans health services"[mh] OR "Hospitals, Veterans"[mh] OR "veterans affairs"[tiab] OR "veterans health"[tiab] OR "veterans choice"[tiab]

AND

Compar*[ti] OR "vs"[ti] OR versus[ti] OR difference[ti] OR "dually enrolled"[tiab] OR "dual system*"[tiab] OR "dual enrollment"[tiab] OR "overlapping use"[tiab] OR (examine*[tiab] AND (access*[tiab] OR availab*[tiab])) OR (("community care*"[tiab] OR "Community Health Services"[Majr]) AND impact*[tiab]) OR ((other[tiab] OR "private sector"[tiab] OR "non-VA"[tiab] OR medicare[tiab] OR "commercially managed"[tiab] OR "non veteran*"[tiab] OR "non VAMC"[tiab] OR "non va"[tiab] OR "non federal hospital*"[tiab] OR "university hospital*"[tiab] OR nonveteran*[tiab] OR "nonfederal hospital*"[tiab]) AND (compar*[tiab] OR comparative study[pt]))

[underlined: Results: 1826]

[underlined: PubMed Update]

[underlined: English; December 2021 to Present]

[underlined: Search run: 9 March 2023]

"United States Department of Veterans Affairs"[mh] OR "Veterans Health"[mh] OR "veterans health services"[mh] OR "Hospitals, Veterans"[mh] OR "veterans affairs"[tiab] OR "veterans health"[tiab] OR "veterans choice"[tiab]

AND

Compar*[ti] OR "vs"[ti] OR versus[ti] OR difference[ti] OR "dually enrolled"[tiab] OR "dual system*"[tiab] OR "dual enrollment"[tiab] OR "overlapping use"[tiab] OR (examine*[tiab] AND (access*[tiab] OR availab*[tiab])) OR (("community care*"[tiab] OR "Community Health Services"[Majr]) AND impact*[tiab]) OR ((other[tiab] OR "private sector"[tiab] OR "non-VA"[tiab] OR medicare[tiab] OR "commercially managed"[tiab] OR "non veteran*"[tiab] OR "non VAMC"[tiab] OR "non va"[tiab] OR "non federal hospital*"[tiab] OR "university hospital*"[tiab] OR nonveteran*[tiab] OR "nonfederal hospital*"[tiab]) AND (compar*[tiab] OR comparative study[pt]))

[underlined: Results: 374]

[underlined: APA PsycINFO]

[underlined: English; 2015 to Present]

[underlined: Publication Limiter: Journal Articles]

[underlined: Search run: 10 March 2023]

TI("Veterans Health" OR "veterans affairs" OR "veterans health" OR "veterans choice") OR AB("Veterans Health" OR "veterans affairs" OR "veterans health" OR "veterans choice")

AND

TI(Compar* OR "vs" OR versus OR difference) OR (TI("dually enrolled" OR "dual system*" OR "dual enrollment" OR "overlapping use") OR AB("dually enrolled" OR "dual system*" OR "dual enrollment" OR "overlapping use")) OR (TI(examine*) AND TI(access* OR availab*)) OR (TI(examine*) AND AB(access* OR availab*)) OR (AB(examine*) AND TI(access* OR availab*)) OR (AB(examine*) AND AB(access* OR availab*)) OR ((TI("community care*") OR AB("community care*") OR MM("Community Mental Health Services")) AND (TI(impact* OR AB(impact*))) OR (TI(other OR "private sector" OR "non-VA" OR medicare OR "commercially managed" OR "non veteran*" OR "non VAMC" OR "non va" OR "non federal hospital*" OR "university hospital*" OR nonveteran* OR "nonfederal hospital*") OR AB(other OR "private sector" OR "non-VA" OR medicare OR "commercially managed" OR "non veteran*" OR "non VAMC" OR "non va" OR "non federal hospital*" OR "university hospital*" OR nonveteran* OR "nonfederal hospital*")) AND (TI(compar*) OR AB(compar*) OR TI("comparative study")))

[underlined: Results: 112]

[underlined: Web of Science]

[underlined: English; 2015 to Present]

[underlined: Search run: 15 March 2023]

TI=("veterans affairs" OR "veterans health" OR "veterans choice" OR "veterans hospital") OR AB=("veterans affairs" OR "veterans health" OR "veterans choice" OR "veterans hospital")

AND

TI=(compar* OR "vs" OR versus OR difference) OR TI=("dually enrolled" OR "dual system*" OR "dual enrollment" OR "overlapping use") OR AB=("dually enrolled" OR "dual system*" OR "dual enrollment" OR "overlapping use") OR ((TI=(examine*) OR AB=(examine*)) AND (TI=(access* OR availab*) OR AB=(access* OR availab*))) OR ((TI=("community care*") OR AB=("community care*")) AND (TI=(impact*) OR AB=(impact*))) OR (TI=(other OR "private sector" OR "non-VA" OR medicare OR "commercially managed" OR "non veteran*" OR "non VAMC" OR "non va" OR "non federal hospital*" OR "university hospital*" OR nonveteran* OR "nonfederal hospital*") OR AB=(other OR "private sector" OR "non-VA" OR medicare OR "commercially managed" OR "non veteran*" OR "non VAMC" OR "non va" OR "non federal hospital*" OR "university hospital*" OR nonveteran* OR "nonfederal hospital*")) AND (TI=(compar*) OR AB=(compar*))

[underlined: Results: 136]

[underlined: Total: 2448]

[underlined: Total after deduplication: 2415]