# ABBREVIATIONS TABLE

AHRQ: Agency for Healthcare Research and Quality
AMI: Acute myocardial infarction
BEST: Beta-blocker Evaluation of Survival Trial
CABG: Coronary artery bypass graft
CAUTI: Catheter-associated urinary tract infection
CC: Community care
CDW: Corporate data warehouse
CKD: Chronic kidney disease
CLC: Community living center
CMS: Centers for Medicare & Medicaid Services
COPD: Chronic obstructive pulmonary disease
CVD: Cardiovascular disease
ED: Emergency department
ER: Emergency room
ESRD: End-stage renal disease
FY: Fiscal year
HCAHPS: Hospital Consumer Assessment of Healthcare Providers and Systems
HF: Heart failure
MISSION: Maintaining Internal Systems and Strengthening Integrated Outside Networks
NCDB: National Cancer Database
NH: Nursing home
NSCLC: Non-small cell lung cancer
NSQIP: National Surgical Quality Improvement Program
PCI: Percutaneous coronary intervention
PCP: Primary care provider
PE: Pulmonary embolism
SEER: SHEP Survey of Healthcare Experience of Patients
THA: Total hip arthroplasty
TKA: Total knee arthroplasty
VA: United States Department of Veterans Affairs
VCP: Veterans Choice Program
VISN: Veterans Integrated Service Network
VTE: Venous thromboembolism